# Summary and Discussion

These evidence maps provide a broad overview of the evidence on clinical aromatherapy and topical EO interventions. We systematically searched the literature for SRs and meta-analyses of these interventions, and we included 25 SRs examining these interventions across a variety of targeted health-related conditions and populations. We compiled evidence maps to illustrate the reported effects of each intervention in the populations studied.

The only condition for which we found a preponderance of evidence suggesting benefit was pain in dysmenorrhea. This was one of the best-studied conditions and we found evidence of positive effects on pain in dysmenorrhea with inhaled EOs with and without massage, with moderate confidence.

We found several areas where EOs are potentially promising for particular populations and/or conditions – including labor/childbirth, hypertension, hemodialysis, stress, perioperative care, and sleep quality – in which inhaled EOs were inconsistently associated with positive effects across studies or across outcomes within a given domain (eg, positive effects for 1 measured psychological outcome but not another, or positive effects in some studies but not a majority). We also found evidence of potential effectiveness in the use of topical tea tree oil for tinea pedis.

However, we found insufficient evidence to characterize treatment effects in most of the conditions studied. The most common reasons we rated evidence as insufficient was a simple paucity of trials, small sample sizes, and methodologic limitations of the studies. On the other hand, aside from low-confidence evidence examining aromatherapy for anxiety in palliative care patients, we found very little evidence with which to characterize aromatherapy as ineffective. In other words, in broad terms, the literature examining aromatherapy does not yet appear to provide enough information to determine whether it has any effects for most conditions.

One challenge in interpreting and applying the aromatherapy literature is the variation in interventions across studies. There are many sources of intervention variation: the compounds used for aromatherapy, their concentrations, the equipment through which they are delivered, the frequency and duration of their application, their combination with co-interventions like massage, and the inhalation instructions provided to patients. In this evidence map, we were unable to determine the comparative effectiveness of different aromatherapy interventions for different conditions. Applying this evidence to clinical settings in the United States is also complicated by the lack of regulatory oversight and standardization of these interventions.

Determining how much of an intervention’s effectiveness is a direct effect of the specific intervention and how much is due to the placebo effect may be less important if the intervention is low cost and has few adverse effects. The costs and cost-effectiveness of EO interventions were beyond the scope of our review, though compared with conventional treatments these are generally considered low-cost interventions. Inhaled-only and topical EO interventions could be administered by a variety of providers in a range of settings, whereas massage would add cost and specialization on the part of the provider.^41,42^ We have very little data about adverse effects from the included reviews, as they were seldom reported. Sensitive populations, such as those with asthma or allergies, may be at potentially greater risk of adverse effects from inhaled or topical EO interventions.^43–45^

## Limitations

There are several limitations related to evidence map methodology and related to the body of evidence itself. These evidence maps provide a broad overview of the existing evidence compiled by SRs. These maps provide only broad “brushstrokes” regarding the potential benefits of these interventions. Evidence maps such as these are not designed to provide definitive conclusions about benefit, and there are several reasons for cautious interpretation: 1) we relied only on SRs and did not search for more recently published trials or conditions for which no SR has been written (so we cannot be definitive in our characterization of the evidence for each condition, nor is this an exhaustive list of conditions/populations for which aromatherapy has been used), 2) we cannot comment on the magnitude of treatment effect, 3) we relied on others’ study quality assessments, and 4) our measure of the level of confidence cannot approach the rigor represented by standardized approaches^46^ given the previously listed constraints. One should be particularly circumspect about the “potential for positive effect” findings since these were – by design – weighted toward identifying any potential area of benefit to aid with research prioritization.

The body of evidence was itself limited in many ways. Many studies in the reviews were rated as having a high risk of bias because they failed to report quantitative measures, used inadequate placebos, or because the interventions were not well standardized. One explanation for the poor study quality provided by some practitioners of aromatherapy is that it does not lend itself well to standardization in the trial setting, because usual practice involves a great degree of personalization of dosage, dilution, and scent.^22,35^ The authors of the included reviews often noted insufficient patient blinding or the use of a non-odor placebo. Attention controls were seldom used.

There were also limitations within the SRs included in this report. Several SRs did not report effect sizes or p-values, stating only the presence or absence of a treatment effect, and whether the finding of difference was statistically significant. We relied on the reporting of the systematic reviews; therefore, it is possible that primary trials included in these reviews reported more detailed analyses, but this would not have been reflected in our report.

## Research Gaps/Future Research

The maps highlight many potential areas for future research. The interventions and health conditions for which there was evidence of a “potential positive effect” may be one place to start to prioritize research, since these findings underscore potentially fruitful areas of research. The comparative effectiveness of different, standardized aromatherapeutic approaches should be examined especially in conditions for which there is potential promise. Future studies should capture potential adverse effects data, and the safety of aromatherapy should be examined in patients with comorbidities especially those of the respiratory tract. The use of a non-EO fragrance comparator would improve blinding and allow comparison of effects and harms of aromatherapy containing EO versus synthetically generated fragrance oils.

## Conclusions

There is moderate confidence that aromatherapy is effective for pain in dysmenorrhea. We found potential positive effects of aromatherapy for pain in labor/childbirth; blood pressure reduction in those with hypertension; stress, depression, and sleep in patients on hemodialysis; stress in healthy adults; anxiety in perioperative patients undergoing various surgery types; and sleep quality in various populations, with low to moderate confidence in the evidence. For EOs applied topically, there is moderate confidence in the potentially positive effect of tea tree oil for tinea pedis. There is insufficient evidence with which to determine whether aromatherapy or topically applied EOs is effective for all other examined conditions.