# Results

## Literature Flow

Our search of electronic databases, bibliographies, and other sources resulted in a total of 1,646 citations. After reviewing titles and abstracts, we included 171 for further screening at the full-text level. Of these, 56 SRs met our inclusion criteria. After reviewing all eligible SRs, we selected 25 SRs representing the most recent and comprehensive evidence available on each health-related condition and/or population (Figure 2).

Figure 2 Literature Flow Chart

Abbreviations: EO = essential oil; SR= systematic review

## KEY QUESTION: What evidence is available that examines the effectiveness of aromatherapy or essential oils for health-related indications?

Twenty-six health-related conditions/target populations were examined by the 25 SRs selected for the evidence map. Twenty-two SRs provide evidence on inhaled EO interventions,^16–37^ which encompass aromatherapy combined with massage (EO-massage) as well as inhaled-only aromatherapy. Three SRs provide evidence on topical EO interventions.^38–40^ One SR of topical EOs for various fungal infections included both tinea pedis and onychomycosis, and we present the findings for these health conditions separately.

Figure 3 shows the number of trials for each health condition according to treatment modality. Evidence from 171 eligible trials is represented among the 25 SRs. Hemodialysis, perioperative patients, dysmenorrhea, labor/childbirth, sleep, anxiety, and depression were the most widely studied conditions/populations. Aromatherapy interventions were most often delivered via inhalation, though the method of application varied widely. Inhaled EO studies used a range of administration methods: the EO could be released to the air by diffusion or vaporization, applied to cotton and attached to the subject’s clothing, inhaled directly from a vessel, applied to the inside of a ventilation mask, or added to the lotion/oil used during massage – all of these were commonly described as aromatherapy. SRs of aromatherapy frequently included trials of aromatherapy-massage (Figure 3), which may involve direct dermal exposure through the addition of EO to massage lotion/oil or may be limited to inhalation only if the EO is diffused in the room during massage. In many cases the SR referred to the intervention simply as “aromatherapy-massage” without specifying whether the exposure was administered via massage oil or diffuser. When details of the methods of the EO-massage trials were provided, dermal contact was the most commonly described exposure method.

Table 3 specifies the outcomes reported for each health condition/target population. The results for these outcomes are presented in Figure 4, a map of the evidence for inhaled EO interventions in 22 health conditions. There is evidence that inhaled EOs are beneficial for pain in dysmenorrhea,^23^ and the level of confidence in the evidence is moderate. Inhaled EOs have potential benefit for physical symptoms during labor/childbirth^26^ (moderate confidence) and for patients with hypertension^25^ (low confidence). Two SRs provided low-confidence evidence of a potential positive effects on sleep quality.^24,35^ There is moderate-confidence evidence that aromatherapy has no effect on anxiety in palliative care.^18^ The effects of inhaled EOs are unclear for nausea/vomiting, and for all other conditions studied.

Figure 5 presents an evidence map for the effects of topical EO interventions for 4 health conditions. There is evidence of potential effectiveness in the use of topical tea tree oil for tinea pedis,^40^ and the level of confidence in the evidence is moderate. The effectiveness of topical EOs is unclear for onychomycosis, acne, and episiotomy wound healing.

Table 3 Populations, health conditions, and/or symptoms addressed in systematic reviews of essential oil interventions

Label used in figures | Comments about study samples | Outcome category | Targeted symptom or measured outcome
Acne^38^ | 1 trial in patients with mild to moderate facial acne vulgaris | Physical | Skin lesion count, acne severity
Anxiety, healthcare waiting spaces^17^ | Samples included patients awaiting dental or surgical procedures | Psychological | Anxiety
Anxiety, palliative care^18^ | Participants included patients rather than caregivers | Psychological | Anxiety
Anxiety, various populations^19^ | Samples included patients with clinical anxiety, other health conditions or settings (eg, cancer, perioperative, ICU, colonoscopy), or healthy volunteers | Psychological | Anxiety
Complications, hemodialysis^24^ | --- | Psychological; Physical; Global; Sleep | Anxiety; depression; stress; Fatigue, pruritis; QOL; Sleep quality
Depressive symptoms, various populations^22^ | Only 1 of 8 eligible studies targeted patients with depression or anxiety. The others enrolled healthy volunteers or those with various health conditions (eg, cancer, pregnancy, postpartum, mothers of children with ADHD) | Psychological | Depressive symptoms measured by various scales
Dysmenorrhea^23^ | --- | Physical | Pain
Nausea/vomiting, postoperative^26^ | Studies of patients undergoing a variety of surgical procedures | Nausea/vomiting | Nausea severity
Nausea/vomiting, early pregnancy^28^ | --- | Psychological; Nausea/vomiting | Satisfaction with treatment; Nausea and vomiting severity; vomiting intensity
Onychomycosis^40^ | --- | Physical | Conversion to negative culture; resolution of symptoms
Pain, hemiplegic shoulder pain after stroke^29^ | --- | Physical | Pain
Pain, postoperative^30^ | Samples included various surgical procedures | Physical | Pain
Perioperative symptoms, various surgery types^31^ | Samples included various surgical procedures | Psychological; Physical; Nausea/Vomiting | Anxiety; Pain; Nausea/Vomiting
Physical symptoms, labor/childbirth^26^ | --- | Physical | Pain, duration of labor, emergency C-section, spontaneous membrane rupture, and spontaneous labor onset
Psychological symptoms, women aged 45+^32^ | Peri- and post-menopausal women | Psychological | Anxiety; depression
SBP/DBP, hypertension^25^ | Patients with hypertension or prehypertension | Physical | SBP, DBP
Sexual symptoms, women aged 45+^33^ | Peri- and post-menopausal women | Psychological | Sexual desire; vaginal dryness during intercourse, avoiding intimacy
Sleep, critical care/ICU^34^ | --- | Sleep | Sleep quality
Sleep, various populations^35^ | Samples included mostly healthy volunteers, and some patients with insomnia or ischemic heart disease | Sleep | Sleep quality
Stress, healthy adults^36^ | --- | Psychological | Stress
Stress, nurses^37^ | --- | Psychological | Work-related stress
Symptom relief, burn patients^20^ | --- | Psychological; Physical; Sleep | Anxiety; Pain; Sleep quality
Symptom relief, cancer^21^ | Samples included patients with various forms of cancer | Psychological; Physical; Global | Anxiety; Pain, mobility, tiredness, and various other physical symptoms (from RSCL); QOL; functioning
Tinea pedis^40^ | ‘--- | Physical | Conversion to negative culture; resolution of symptoms
Various symptoms, dementia^16^ | ‘--- | Psychological; Global | Behavioral and psychological symptoms of dementia (BPSD); cognitive function; agitation; resistance to taking medication; relationship with caregiver; ADL; QOL
Wound healing, episiotomy^39^ | ‘--- | Physical | Redness; edema; ecchymosis; discharge; approximation; exudation; dyspareunia

Abbreviations: ADL = activities of daily living; BPSD = Behavioral and psychological symptoms of dementia; DBP = diastolic blood pressure; EO = essential oil; QOL = quality of life; RSCL = Rotterdam Symptom Checklist; SBP = systolic blood pressure; SR = systematic review

Note: All studies in a review may not have addressed each population or condition

Figure 3 Number of trials of essential oil interventions for targeted health conditions/populations, by treatment modality

Figure 4 Map of the evidence from systematic reviews of inhaled essential oils for targeted health conditions/populations

### Inhaled EO interventions - Psychological outcomes

Seven SRs examined the effects of inhaled EOs on anxiety and reported mixed findings. Table 4 provides a summary of the findings. An SR of hemodialysis patients found potential positive effects on anxiety, depression, and stress,^24^ and an SR of perioperative patients found a potential positive effect on reducing anxiety.^31^ The level of confidence in these findings was low. A meta-analysis of 3 RCTs found no effect on anxiety in palliative care (low confidence).^18^ Evidence of effectiveness for anxiety was unclear for waiting room settings,^17^ burn patients,^20^ cancer,^21^ hemodialysis,^24^ women aged 45+,^32^ and in an SR of various populations.^19^

Of 3 SRs that examined stress, 2 found evidence of a potential positive effect (low confidence) in healthy adults^36^ and hemodialysis patients.^24^ Evidence of effect was unclear in an SR of occupational stress among nurses.^37^

The effects of inhaled EO interventions on depression, behavioral problems in dementia, and other psychological outcomes were also unclear (Table 4).

Table 4 Psychological health outcomes in systematic reviews of inhaled essential oil interventions

Health condition, population; N trials (N pts); EO modality | Findings | Overall effect | Level of confidence
Anxiety, healthcare waiting spaces^17^; 5 RCTs (N=793); 1 CCT (N=72); Inhaled | [underlined: Anxiety in health care waiting rooms (5 RCTs, N=793; 1 CCT N=72):] Mixed findings.; 2 low-ROB RCTs of dental patients (N=219 and N=340): reduction in anxiety in 1, no difference in the other.; 3 unclear-ROB RCTs of pts awaiting surgical procedures (N=234): significant reduction with aromatherapy, although 1 RCT included the effect of a soothing nature DVD. Effect sizes and p-values NR.; 1 CCT of pts awaiting surgery (N=72): STAI score 11.0(±2.2) points lower with AT after waiting period, P-value NR. | Unclear | Insufficient
Anxiety, palliative care^18^; 3 RCTs (N=160); of EO-massage | [underlined: Anxiety (3 high-ROB RCTs; N=160):] No difference; Anxiety by STAI (MD= −2.60 [95% CI: −7.82 to 2.63], P = 0.33). Heterogeneity NS (x^2^=2.31, P=0.31, I^2^=13%). | No effect | Low
Anxiety, various populations^19^; 11 RCTs (N=1,076); Inhaled only: 9 RCTs; EO-massage: 2 RCTs Lavender | [underlined: Anxiety (9 high-ROB RCTs, N=964):]; 3 RCTs favored Tx (P ≤ 0.05 reported), 6 RCTs found no effect. Effect sizes and P-values NR.; [underlined: Stress (3 high-ROB RCTs, N=152):] Significant reduction in 1 RCT (N=42, P < 0.01), 2 RCTs found no effect. Effect sizes NR. | Unclear | Insufficient
Symptom relief, burn patients^20^; 4 RCTs (N=248); Inhaled; Lavender and/or rose | [underlined: Anxiety (2 high-ROB RCTs; N=110):] Mixed findings.; 1 RCT (N=60) found significant benefit: STAI −0.93 [95% CI −1.46 to - 0.39], P=0.0007; 1 RCT (N=60) found no effect: STAI −0.46 [95% CI −0.97 to 0.05] | Unclear | Insufficient
Symptom relief, cancer^21^; 2 RCTs (N=139) of EO-massage | [underlined: Anxiety immediately following massage (2 high-ROB RCTS, N=139):] Mixed effects. 1 RCT (N=52) Unclear found significantly greater reduction in massage-only control. 1 RCT (N=87) found benefit in both T and C. Effect sizes NR; differences between groups NR.; [underlined: Anxiety longer-term (2 high-ROB RCTS, N=139):] Mixed findings.; 1 RCT (N=52) found no differences between groups. 1 RCT (N=87) found improvement on RSCL subscales: psychological (P < 0.01), severe psychological (P < 0.01); no significant change in anxiety with massage-only. Effect sizes NR; differences between groups NR. | Unclear | Insufficient
Various symptoms, dementia^16^; 10 RCTs (N=363); 8 Inhaled-only; 2 Massage-EO | [underlined: BPSD:]; 2 unclear-ROB RCTs (N=91) found greater reduction in BPSD in Tx group, effect sizes NR. 1 RCT reported P<0.01; P-value NR in 1 RCT.; [underlined: Cognitive function (1 high-ROB RCT, N=28):] Significant improvement in Tx group. Effect size and P-value NR.; [underlined: Agitation]: Mixed findings.; 2 RCTs found significant reduction: 1 low-ROB RCT (N=72) effect size and P-value NR; 1 unclear-ROB RCT (N=70) significant reduction on agitation and other symptoms (P < 0.01); 2 RCTS found no difference: 1 low-ROB RCT (N=114) and 1 high-ROB RCT (N=7). Effect size and P-values NR.; [underlined: Resistance to taking medication (1 high-ROB RCT, N=13):] No difference. Effect size and P-value NR.; [underlined: Relationship with caregiver (1 high-ROB RCT, N=16):] Positive improvement. Effect size and P-value NR. | Unclear | Insufficient
Depressive symptoms, various populations^22^; 8 RCTs (N=858); Inhaled only: 5 RCTs; EO-massage: 3 RCTs | [underlined: Improvement in depressive symptoms (8 RCTS; N = 858):]; [underlined: EO inhaled only (5 RCTs, N=694):] Mixed findings.; In 1 high-ROB RCT of 40 healthy volunteers: change in TMD score −1.28 ± 2.6 vs 0.5 ± 2.2 (P<0.05). In 1 high-ROB RCT of 28 postpartum women: mean difference in EPDS scores at end point was −3.981 (P = NS).; 1 Unclear RCT in 13 pregnant women and 2 Low-ROB RCTs (313 cancer pts receiving radiotherapy and 320 pregnant women) found no stat. sig. differences.; [underlined: EO massage (3 RCTs, N=164):] Mixed findings.; 1 high-ROB RCT in 32 pts with depression and/or anxiety found benefit: baseline/endpoint MADRS scores: 30/18.1 vs 19.8/21.1 (P<0.05).; 1 low-ROB RCT in 42 cancer pts and 1 high-ROB RCT in 90 women aged 45–60 found no stat. sig differences. | Unclear | Insufficient
Complications, hemodialysis^24^; 15 RCTs (N=865); 7 CCTs (N=332); Inhaled only: 14 RCTs and 2 CCTs; EO-massage: 1 RCT and 5 CCTs | Mixed findings with preponderance of benefit. Effect sizes and P-values NR.; [underlined: Anxiety (6 unclear-ROB RCTs; N=335):] 5 RCTs favor tx; 1 found no effect.; [underlined: Depression (3 unclear-ROB RCTs; N=192):] All 3 favor tx; 1 RCT found significant positive effect on depression but no effect on anxiety.; [underlined: Stress (2 unclear-ROB RCTs; N=120):] Both favor tx. | Potential positive | Low
Early pregnancy^28^; 1 unclear-ROB RCT, N=100; Inhaled-only; Lemon oil | [underlined: Satisfaction with treatment:] No difference. MD = 1.47 (95% CI: 0.91 to 2.37), P = 0.11 | Unclear | Insufficient
Perioperative symptoms, various surgical procedures^31^; 14 RCTs (N=1,571); 4 CCTs (N=342); Inhaled-only except for 1 RCT (Massage-EO) | [underlined: Anxiety reduction, various surgery types: 4 RCTs (N=336)]; Mixed findings with potential positive effects.; 1 low-ROB RCTs (N=109) found significant difference in STAI: −3 vs −2 (P = 0.02).; 1 low-ROB RCT (N=60) found no sig. differences in STAI at any timepoint (12.6 vs 42.73 after intervention; 41.33 vs 41.56 at 3d post-op).; 1 high-ROB RCT (N=87) found reduction in STAI (48 to 37) with lavender-sandalwood (P=0.03 vs placebo 43 to 39) but not with orange-peppermint (43 to 37).; 1 CCT of 72 cardiac and general surgery pts found significant improvement: STAI −12.4 vs −2.4 (P < 0.01). | Potential positive | Low
Psychological symptoms, women aged 45+^32^; 4 RCTs (N=296); Inhaled : 2 RCTs; EO-massage: 2 RCTs | [underlined: Short-term effect on psychological symptoms (anxiety and depression; 4 high-ROB RCTs, N=296):] Multiple dissimilar rating scales for outcomes were reported in MA, therefore effect was rated unclear. | Unclear | Insufficient
Sexual symptoms, women aged 45+^33^; 2 RCTs (N=181); Inhaled only | [underlined: Sexual desire (1 high-ROB RCT; N=100):] significantly improved with lavender. Effect size and P-value NR.; [underlined: MENQOL - sexual domain (1 unclear-ROB RCT, N=81):] Significant improvement with neroli oil.; Effect size and P-value NR; . | Unclear | Insufficient
Stress, healthy adults^36^; 4 RCTs (N=123) of inhaled only | [underlined: Subjective stress level (MA of 3 RCTs, 2-high ROB, 1 unclear-ROB, N = 80):] Favors treatment.; SMD = −0.96 (95% CI: −1.44 to −0.48), Z = 3.93, P < 0.0001; heterogeneity: I^2^= 0%, P = 0.58.; Another high-ROB RCT (N=30) not included in MA found no difference. | Potential positive | Low
Stress, nurses^37^; 1 RCT (N=32) of EO-massage; 3 CCTs (N=195 of inhaled only) | [underlined: Work-related stress 1 high-ROB RCT (N=32), 3 CCTs (N=195)]: 1 6-wk RCT found significant interaction between time and group (P < 0.05). 1 CCT (N=110) found reduction on days 3–4 of 4-day trial. 1 CCT (N=14) found mixed results. Effect sizes and P-values NR in the CCTs.; 1 CCT (N=71) found no effect on workplace stress. | Unclear | Insufficient

Abbreviations: BPSD = Behavioral and Psychological Symptoms of Dementia; CCT = clinical controlled trial; EO = essential oil; EPDS = Edinburgh Postnatal Depression Scale; MA = meta-analysis; MADRS = Montgomery–Åsberg Depression Rating Scale; MD = mean difference; MENQOL = Menopause-specific Quality of Life Questionnaire; NR = not reported; NS = not significant; P = p-value; PBO = placebo; pts = participants; RCT = randomized controlled trial; ROB = risk of bias; RR = risk ratio; RSCL = Rotterdam Symptom Checklist; SMD = standard mean difference; STAI = State-Trait Anxiety Inventory; TMD = Total Mood Disturbance; tx = treatment.

### Inhaled EO interventions – Nausea/vomiting

Three SRs provided data on the effects of inhaled EOs on nausea/vomiting (see Table 5 for a summary of findings). SRs in perioperative^31^ and postoperative^27^ patients reported mixed findings. An SR of aromatherapy during pregnancy also reported mixed findings. The overall effectiveness for nausea/vomiting was unclear in all 3 reviews.

Table 5 Effects of inhaled EO interventions on nausea/vomiting

Target population; N trials (N pts); EO modality | Findings on nausea/vomiting | Overall effect | Level of confidence
Perioperative symptoms, various surgical procedures^31^; 6 high-ROB RCTs,; N=901;; 1 CCT, N=60; 1 CCT, NInhaled-only | 1 CCT, NVarious EOs and measures used among trials; peppermint oil used most commonly.; Mixed findings:; 4 RCTs and 1 CCT reported statistically significant positive effects.; 2 RCTs reported null effects.; Unclear effect reported in 1 CCT. | Unclear | Insufficient
Postoperative^27^; 4 high-ROB RCTs; (N=115); Inhaled-only | MA of 4 RCTs of peppermint oil,; Nausea severity at 5 minutes post-initial treatment: no difference; SMD = −0.18 (95% CI: −0.86 to 0.49).; Significant heterogeneity: I^2^ = 66% (P = 0.03) | Unclear | Insufficient
Early pregnancy^28^; 2 RCTs (N=160); Inhaled-only | Mixed effects:; 1 unclear-ROB RCT (N=100) of lemon oil:; PUQE score on day 3 of intervention: no effect, mean difference −0.46 (95% CI: −1.27 to 0.35), P=0.27; PUQE scores from baseline to day 3 of intervention:; Significant improvement;; mean difference −1.50 (95% CI −2.41 to −0.59), P=0.0012; 1 high-ROB RCT (N=60) of mint oil:; Severity of nausea on day 4: no effect:; mean difference −0.88 (95% CI: −1.93 to 0.17), P=0.099; Vomiting intensity on day 4: no effect,; mean difference −0.32 (95% CI: −1.45 to 0.81), P=0.58 | Unclear | Insufficient

Abbreviations: CCT = clinical controlled trial; EO = essential oil; MA = meta-analysis; NR = not reported; NS = not significant; P = p-value; PBO = placebo; pts = participants; PUQE = Pregnancy-Unique Quantification of Emesis/Nausea; RCT = randomized controlled trial; ROB = risk of bias; SMD = standard mean difference.

### Inhaled EO interventions – Pain and other physical signs/symptoms

Seven SRs reported pain outcomes in trials of inhaled EO interventions. Table 6 provides a summary of the findings. An SR of dysmenorrhea found statistically significant effects on pain reduction in a meta-analysis of 7 RCTs of inhaled-only EO (SMD = −1.02, 95% CI −1.59 to −0.44) and in a meta-analysis of 11 RCTs of EO-massage (SMD = −0.87, 95% CI −1.14 to −0.60), although there was significant heterogeneity in both analyses.^23^ The overall effect was positive and the level of confidence was moderate, in part due to the large number of trials (17) and combined sample size (N=1,534).

There was evidence of a potential positive effect on labor pain,^26^ and the level of confidence was moderate.

Inhaled EO was associated with reduced systolic and diastolic blood pressure in patients with hypertension, based on evidence from a small high-ROB RCT and 4 CCTs.^25^ Given limitations in the study methods, we rated the evidence of effectiveness for hypertension as potential positive, with a low level of confidence.

Table 6 Effects of inhaled EO interventions on pain and other physical signs/symptoms

Health condition, population; N trials (N pts); EO modality | Findings | Overall effect | Level of confidence
Symptom relief, burn patients^20^; 4 RCTs (N=248); Inhaled lavender and/or rose | [underlined: Pain (2 high-ROB RCTs; N=110):] significant effect in both. 1 RCT (N=50) effect estimate: −1.22 [95% CI −1.83 to −0.61], P<0.0001; 1 RCT (N=60) effect estimate:; −0.67 [95% CI −1.19 to −0.14], P=0.01.; SR authors note heterogeneity in study characteristics, evidence insufficient for concluding effectiveness. | Unclear | Insufficient
Symptom relief, cancer^21^; 2 RCTs (N=139) of EO-massage | [underlined: Pain, mobility, tiredness (1 high-ROB RCT; N=52):] No difference between groups.; [underlined: Physical symptoms (1 high-ROB RCT; N=87):] Within tx group improvement on physical (P < 0.05) and severe physical symptoms (P < 0.001) on RSCL subscales. Effect sizes NR; differences between groups NR. | Unclear | Insufficient
Dysmenorrhea^23^; 17 RCTs (N=1,534); Inhaled only: 7 RCTs; EO-massage: 11 RCTs (1 RCT of both inhaled EO-massage) | [underlined: Pain in RCTs of Inhaled EO (7 RCTs, 2 low-ROB, 5 unclear-ROB, N = 817):] SMD −1.02 (95% CI: −1.59 to −0.44), significant heterogeneity I^2^ = 95% (P<0.0001); [underlined: Pain in RCTs of EO Massage (11 RCTs, 1 low-ROB, 10 unclear-ROB, N = 791):] SMD −0.87 (95% CI: −1.14 to −0.60), significant heterogeneity I^2^ = 70% (P = 0.0001) | Positive | Moderate
Complications, hemodialysis^24^; Fatigue: 4 RCTs (N=201); Inhaled-only; Pruritus: 4 CCTs (N=163); EO-massage | [underlined: Fatigue (2 low-ROB and 2 unclear-ROB RCTs; N=201): Mixed findings.]; Lavender had a positive effect on fatigue reducing fatigue in 2 RCTs (1 low-ROB, 1 unclear-ROB. 2 other RCTs (1 low-ROB, 1 unclear-ROB) found lavender had no effect. Effect sizes and P-values NR.; [underlined: Pruritus: 4 CCTs (N=163):] reported a positive effect on reducing pruritus. Effect sizes and P-values NR. No data from RCTs. | Unclear | Insufficient
SBP/DBP, hypertension^25^; 1 RCT (N=30), 4 CCTs (N=170); Inhaled only: 1 RCT and 3 CCTs; EO-massage: 1 CCT | [underlined: SBP (1 high-ROB RCT, N=30; 4 CCTs, N=170):] significant decrease P < 0.00001 in RCT; 2 CCTs (N=103) found significant decrease; 2 CCTs (N=67) no data.; [underlined: DBP (1 high-ROB RCT, N=30; 4 CCTs, N=170):]; Significant decrease in 1 RCT, P < 0.00001; 2 CCTs (N=103) found significant decrease, 2 CCTs (N=67) no data. | Potential positive | Low
Physical symptoms, labor/childbirth^26^; 17 RCTs (N=1,926); Inhaled only: 11 RCTs; EO-massage: 6 RCTs | [underlined: Pain:]; Pain score in trials with dilation info (6 RCTs, 1 high-, 5 unclear-ROB; N=656 baseline; 652 post): baseline ND (MD=0.09[−0.12 to 0.30]; Z=0.86 [P=0.39]); post-intervention significant reduction (MD=−0.82 [−1.55 to −0.09]; Z=2.21 [P=0.03]); Pain score in trials without dilation info (4 RCTs, 2 high-, 2 unclear-ROB; N=364): baseline ND (MD=−0.09 [−0.37 to −0.19]; Z=0.62 [P=0.53]); post-intervention significant reduction (MD=−2.01 [−3.63 to −0.39]; Z=2.43 [P=0.02]); [underlined: Duration of labor:]; Total First-stage labor duration (4 RCTs, 2 high-, 2 unclear-ROB; N=737): No difference (MD=−0.62 [−1.70 to 0.47]; Z=1.11 [P=0.27]); Active First-stage labor duration (6 RCTs, 1 low-, 5 unclear-ROB; N=531): Significantly shorter (MD=−0.69[−1.02 to −0.36]; Z=4.08 [P<.0001]); Second stage labor duration (10 RCTs, 3 high-, 7 unclear-ROB; N=1,246): No difference (MD=−3.92[−8.42 to 0.58]; Z=1.71 [P=0.09]); Third stage labor duration (4 RCTs, 1 high-, 3 unclear-ROB; N=228): Significantly shorter (MD=−3.32[−6.26 to −0.38]; Z=2.21 [P=0.03]); [underlined: Other outcomes:]; Incidence of emergency C-section (6 RCTs, 1-high-, 1-low, 4 unclear-ROB; N=988): No difference (RR=0.78 [0.48 to 1.26]; Z=1.01 [P=0.31]); Incidence of spontaneous membrane rupture (2 RCTS, 1 high-, 1unclear-ROB; N=573): No difference (RR=1.00 [0.64 to 1.56]; Z=0.01 [P=0.99)); Incidence of spontaneous labor onset (2 RCTS, 1 high-, 1unclear-ROB; N=573): No difference (RR=0.99 [0.89 to 1.10]; Z=0.19 [P=0.85]) | Potential positive | Moderate
Pain, hemiplegic shoulder pain after stroke^29^; 1 RCT (N=30); Inhaled + acupressure (vs acupressure) | [underlined: Pain:] 1 unclear-ROB RCT, N = 30 of aromatherapy plus acupressure vs acupressure control (20 min 2x daily for 14 days) Positive effect on mean (3 days) pain score: −1.936 (95% CI: −2.788 to −1.085) | Unclear | Insufficient
Pain, postoperative^30^; 6 RCTs (N=474); Inhaled only: 5 RCTs; EO-massage: 1 RCTs | [underlined: Pain (6 RCTs; N=474):] 2 RCTs (1 high-,1 unclear-ROB; N=104), found no difference. 4 RCTs (2 high-, 2 unclear-ROB; N=373) found greater decrease with AT. Effect size and P-value NR. | Unclear | Insufficient
Perioperative symptoms, various surgical procedures^31^; 14 RCTs (N=1,571); 4 CCTs (N=342); Inhaled-only except for 1 RCT (Massage-EO | [underlined: Pain (various surgery types; 5 RCTs, N=414; 1 CCT, N=40):] Mixed findings.; 4 high-ROB RCTs (N=354) reported significant benefit on various pain measures (10-pt VAS or NAS most commonly) at time points from 5 min to 16 h post-op.; 1 low-ROB RCT (N=60, vitrectomy) reported similar reductions on day 1 between massage-EO (eucalyptus-lemon oil) vs neutral oil: FPS score for shoulder −1.1 vs −0.8, neck −0.85 vs −0.8, back −0.75 vs −0.6. P-values NR.; No sig diff in NAS reduction in 1 CCT of 40 cardiac surgery pts: 5.6 to 5.0 after lavender inhalation, P = NS. | Unclear | Insufficient

Abbreviations: AT = aromatherapy; CCT = clinical controlled trial; DBP = diastolic blood pressure; EO = essential oil; FPS = Faces Pain Scale; h = hours; MA = meta-analysis; NAS = numerical analog scale; NR = not reported; NS = not significant; P = p-value; PBO = placebo; pts = participants; RCT = randomized controlled trial; ROB = risk of bias; RSCL = Rotterdam Symptom Checklist; SBP = systolic blood pressure; SMD = standard mean difference; SR = systematic review; tx = treatment; VAS = visual analog scale.

### Inhaled EO interventions – Sleep quality

The effects of inhaled EOs on sleep quality were reported in 4 SRs. Table 7 provides a summary of the findings. Potential positive effects were reported in 2 SRs. Evidence of effectiveness in 2 other SRs was unclear.

An SR of inhaled EO in hemodialysis patients provided evidence from 4 trials that suggested a potential positive effect on sleep quality,^24^ though the confidence in the evidence was low. Another SR examined the use of aromatherapy for sleep promotion in a variety of populations that included patients with a health condition as well as healthy volunteers.^35^ Among the 9 trials identified, 6 reported statistically significant improvements in sleep quality. The preponderance of benefit suggests a potential positive effect, although methodological limitations in the trials rendered the level of confidence low.

An SR of non-pharmacological interventions for sleep promotion in critical care patients identified 1 RCT (N=25) of aromatherapy, and found no evidence of benefit.^34^ Because the evidence is based on only 1 small trial, the level of confidence in this finding is unclear/insufficient. An SR of aromatherapy for symptom relief in burn patients provided data from an RCT comparing lavender with music therapy, which also provided unclear evidence of effectiveness.^20^

Table 7 Sleep quality in systematic reviews of inhaled essential oil interventions

Population; N trials (N pts) | Intervention characteristics | Findings | Summary of effect | Level of confidence
Burn patients^20^; 1 unclear-ROB; RCT (N=48) | 7 drops of 10% lavender vs music therapy for 20 min, 3 nights | Lavender vs music therapy, sleep quality VAS: 0.48 [95% CI −1.05 to 0.09] | Unclear | Insufficient
Hemodialysis^24^; 2 low-ROB and 1 unclear-ROB; RCTs (N=182); 1 CCT (N=53) | Lavender or orange EO applied near patient (eg, to patient’s collar; cotton ball 68 inches from pillow; or gauze bandage 2 inches from nose). Variation in exposure: 1 RCT during hemodialysis; 1 RCT and 1 CCT throughout the night; 1 RCT not specified | Preponderance of benefit; heterogeneity in timing and methods of EO exposure. Effect sizes and P-values NR. | Potential positive | Low
Critical care/ICU^34^; 1 high-ROB; RCT (N=25) | 1 drop of lavender oil vs 1 drop distilled water applied to pillowcase for 1 night each; 15 hours washout between | No between-group differences in RCSQ sleep scores: mean 59.84 (2.91) vs 63.28 (2.48), P-value NS. | Unclear | Insufficient
Various populations^35^; 9 unclear/high-ROB RCTs (N=265); 4 CCTs (N=58) | Various methods and durations, such as Aromastream device used continuously through the night in 1 RCT; vial held 3 inches from nose for 3 minutes in another RCT. Lavender oil used most frequently. | Mixed findings with preponderance of benefit. 1 RCT of peppermint, 1 RCT of jasmine, and 4 RCTs of lavender, found statistically significant results for improved sleep quality. Effect sizes NR. | Potential positive | Low

Abbreviations: AT = aromatherapy; CCT = clinical controlled trial; EO = essential oil; NR = not reported; NS = not significant; P = p-value; PBO = placebo; pts = participants; RCSQ = Richards-Campbell Sleep Questionnaire; RCT = randomized controlled trial; ROB = risk of bias; VAS = visual analog scale.

### Inhaled EO interventions – Global outcomes

Global outcomes were seldom reported among the SRs of inhaled EO interventions. Three SRs provided data on global outcomes from 3 RCTs and 2 CCTs. Table 8 presents a summary of the findings. The effects of inhaled EO on global outcomes were unclear in patients with cancer,^21^ dementia,^16^ and hemodialysis.^24^ The evidence is insufficient for drawing conclusions.

Table 8 Global outcomes reported in systematic reviews of inhaled EO interventions

Health condition; N trials (N pts); EO modality | Findings | Overall effect | Level of confidence
Cancer ^21^; 2 RCTs (N=139) of EO-massage | [underlined: Function (1 high-ROB RCT; N=52):] Within tx group effect (P<0.03), but no significant differences between groups.; [underlined: QOL (1 high-ROB RCT; N=87):] Tx group improved on RSCL subscales (P < 0.001); no significant changes for massage-only control. Effect sizes NR. | Unclear | Insufficient
Dementia^16^; 1 low-ROB RCT(N=114) of EO-massage; 1 CCT (N=7) of inhaled-only | [underlined: ADL]: Mixed findings.; No difference in 1 low-ROB RCT (N=114) of 10% Melissa oil massaged into hands and upper arms 1–2 min 2x daily for 12 weeks.; Benefit found in 1 CCT (N=7), EO applied every 3 hrs. to sachet pinned to shirt collar, 2 weeks each of lavender and thyme.; 6 Pts required less assistance with ADL tasks. Effect size and P-values NR.; [underlined: QOL:] (1 low-ROB RCT, N=114); Favors Tx (P < 0.05). Effect size NR. | Unclear | Insufficient
Hemodialysis^24^; 1 CCT (N=80); Inhaled-EO | 1 CCT (N=80) used wet wipes scented with chicory essence, applied to patients’ hands and faces 3x per day.; Significant positive effect on SF-36 QOL. Effect sizes and P-values NR. No data from RCTs. | Unclear | Insufficient

Abbreviations: ADL= activities of daily living; CCT = clinical controlled trial; EO = essential oil; hrs. = hours; RSCL = Rotterdam Symptom Checklist; QOL = quality of life; NR = not reported; NS = not significant; P = p-value; RCT = randomized controlled trial; ROB = risk of bias; Tx = treatment.

### Inhaled EO interventions – Adverse effects

The occurrence or absence of adverse effects of inhaled EO interventions was reported in only 2 SRs. An SR of anxiety among various populations^19^ reported that no adverse effects occurred in an RCT of 122 intensive care unit (ICU) patients administered EO-massage with lavender versus carrier oil for 30 minutes, or in an RCT of 340 patients awaiting a dental appointment who were exposed to lavender oil using a candle burner. An SR of aromatherapy for dementia^16^ reported adverse effects from 2 trials of EO-massage: In an RCT of 114 patients, 2 patients treated with massage using Melissa oil had unspecified serious adverse events; and 1 small RCT (N=7) reported the occurrence of allergic reactions from EO-massage (number of patients not specified), and 1 participant reported drowsiness.

### Topical EO interventions

Three SRs of topical EO interventions provided evidence on acne,^38^ fungal infections,^40^ and wound healing in episiotomy.^39^ Figure 5 and Table 9 present the findings on effectiveness and harms.

The SR of fungal infections,^40^ reported mixed findings with a preponderance of benefit in 3 trials of topical EOs for treating tinea pedis. The overall evidence suggested a potential positive effect, and the level of confidence was moderate. The same SR included a trial of tea tree oil versus clotrimazole for onychomycosis, the findings of which were inconclusive.

Significantly positive findings for acne^38^ and wound healing in episiotomy^39^ were reported, but because in each case the evidence was based on a single trial (N<100), the level of confidence was insufficient. The overall effect was therefore rated unclear for these health conditions.

Figure 5 Map of the evidence from systematic reviews of topically applied essential oils for targeted health conditions

Table 9 Findings from systematic reviews of topical essential oil interventions

Health condition; N trials (N pts); EO if specified | Findings | Overall effect | Level of confidence
Acne^38^; 1 unclear-ROB RCT (N=60); Tea tree oil, 5% | [underlined: Total skin lesion counts at 45 days:]; Favors TTO, mean difference −7.53 (95% CI: −10.40 to −4.66); [underlined: Change of acne severity score at 45 days]:; Favors TTO, mean difference −5.75 (95% CI −9.51 to −1.99) | Unclear | Insufficient
Acne^38^; 1 unclear-ROB RCT (N=60); Tea tree oil, 5% | [underlined: Harms,] TTO vs placebo:; Minimal pruritus occurred in 3/30 (10%) vs 2/30 (6.7%).; Mild burning sensation on the skin area where the oil was applied: 1/30 (3.3%) vs 2/30 (6.7%).; Minimal scaling 1/30 (3.3%) vs 0 (0%) | Unclear | Insufficient
Wound healing, episiotomy^39^; 1 unclear-ROB RCT (N=60); Lavender/ thymol (2%) | REEDA healing scale 7 days after episiotomy: significant improvement (P = 0.013); also, significant reductions in hyperemia (P = 0.027); edema (P = 0.027); exudation (P = 0.016); dyspareunia: 2.7 ±1.5 vs 5.3 ±2.7 (P < 0.001).; No significant effect on ecchymosis; border approximation (effect size and P-values NR). | Unclear | Insufficient
Wound healing, episiotomy^39^; 1 unclear-ROB RCT (N=60); Lavender/ thymol (2%) | [underlined: Harms:] systematically reviewed, none reported. | Unclear | Insufficient
Onychomycosis^40^; 1 low-ROB RCT (N=117); Tea tree oil | 100% TTO vs 1% clotrimazole (2x daily for 6 months), no placebo arm.; [underlined: Conversion to negative culture]: 18% vs 11%.; [underlined: Full or partial resolution of symptoms]: 60 vs 61%, declining to 56 vs 55% 3 months later.; Topical clotrimazole has low effectiveness in practice. Therefore, overall effect is unclear. | Unclear | Insufficient
Onychomycosis^40^; 1 low-ROB RCT (N=117); Tea tree oil | [underlined: Harms]: occurred in 5 vs 3 patients (TTO vs clotrimazole, total N=117, randomized per group NR). | Unclear | Insufficient
Tinea pedis^40^; 2 RCTs of tea tree oil:; 1 low-ROB (N=158); 1 unclear-ROB (N=121); 1 CCT (N=70) of bitter orange oil (OBO) | [underlined: Conversion to negative culture (2 RCTs of TTO, N=279):] Mixed findings. Significantly higher cure rates at both 25% and 50% TTO 2x daily for 4 wks. vs placebo in 1 low-ROB RCT (N=158); no difference between 10% TTO 2x daily for 4 wks. vs placebo in 1 unclear-ROB RCT (N=121).; [underlined: Clinical assessment (2 RCTs of TTO, N=279):]; TTO superior to placebo in improvement of symptoms in 1 low-ROB and 1 unclear-ROB RCT.; [underlined: 1 CCT (N=70) of OBO:] 3 arms of different OBO preparations produced more rapid cure rates vs. imidazole; after 2 wks. 93% were cured using 100% OBO, 80% cured using 25% OBO, and 50% using 20% OBO; vs 0% cured using placebo (P-values NR). | Potential positive | Moderate
Tinea pedis^40^; 2 RCTs of tea tree oil:; 1 low-ROB (N=158); 1 unclear-ROB (N=121); 1 CCT (N=70) of bitter orange oil (OBO) | [underlined: Harms:] 1 unclear-ROB RCT (N=121) reported that no adverse effects occurred in the TTO group. | Unclear | Insufficient

Abbreviations: CCT = non-randomized controlled clinical trial, NR = not reported, OBO = bitter orange oil, REEDA = Redness, Edema, Ecchymosis, Discharge, Approximation; RCT = randomized controlled trial, ROB = risk of bias, TTO = tea tree oil.