# Methods

## Topic Development

This topic was nominated by Dr. Peter Glassman, Chair of the Medical Advisory Panel, Pharmacy Benefits Management Service, in conjunction with Dr. Benjamin Kligler, National Director for the Integrative Health Coordinating Center, Patient-Centered Care & Cultural Transformation (OPCC&CT). The scope was refined through a process that included a preliminary review of published peer-reviewed literature and consultations with our operational partners and a panel of technical experts. The research question for this evidence map was: What evidence is available that examines the effectiveness of aromatherapy or essential oils for health-related indications? Our approach to the research question is shown below in Figure 1.

Figure 1 Analytic framework

## Search Strategy

We conducted a comprehensive search for systematic reviews (SRs) and meta-analyses of EO interventions. We consulted with a research librarian to develop the search strategy, and a second research librarian peer-reviewed the search strategy using the instrument for Peer Review of Search Strategies.^13^ The search of electronic databases queried Ovid MEDLINE Epub Ahead of Print, In-Process & Other Non-Indexed Citations, Ovid MEDLINE Daily and Ovid MEDLINE, Ovid PsycINFO, CINAHL, Epistomonikos, and Ovid EBM Reviews Cochrane Database of Systematic Reviews (CDSR, DARE, HTA, and Cochrane CENTRAL), and included all available years of publication from database inception (1946 for Ovid MEDLINE®) through February 2019; Appendix A provides the search strategies for each database. We further examined the bibliographies of relevant publications, searched the PROSPERO registry for completed systematic reviews, and consulted subject matter experts for potentially relevant studies.

## Study Selection

We applied pre-specified selection criteria (Appendix B) to assess the titles and abstracts yielded by the literature search. We used Abstrackr,^14^ an online tool for screening citations, and retrieved potentially relevant articles for review at the full-text level. Two investigators independently assessed all abstracts and full-text articles for inclusion and resolved disagreements through discussion and consensus.

We selected SRs and meta-analyses that included randomized controlled trials (RCTs) of clinical aromatherapy or topically applied essential oils for specific health indications, risk populations, or targeted settings such as healthcare waiting spaces.

We excluded reviews examining only children or adolescents. If an eligible SR included both pediatric and adult populations, we abstracted data from only the trials in adults.

We classified aromatherapy-massage (EO-massage) as an inhaled modality, and only included data from trials that included a massage-only control group. We similarly included data from 1 trial of aromatherapy combined with acupressure that included an acupressure-only control group. We excluded data from trials that did not control for concurrent interventions.

We excluded data from interventions in which oral or mucous membranes made direct contact with EOs, such as mouth rinses, vaginal applications, or orally ingested EO formulations. Table 1 specifies the criteria for population, interventions, comparators, outcomes, timing, and setting (PICOTS).

Table 1 PICOTS

Key Question | What evidence is available on the effectiveness of aromatherapy or essential oils for health-related conditions?; ▪ In which health conditions/target populations have they been studied?; ▪ Which formulations have been studied?; ▪ What is the effect of the intervention in each health condition studied? 4 effect categories:; - No effect; - Unclear; - Potential positive; - Positive; ▪ What is the level of confidence in the evidence for that effect? 4 confidence levels:; - Insufficient; - Low; - Moderate; - High
Population | Adults (18+) receiving an EO intervention for a targeted health condition or risk group.
Interventions | Include: Essential oil preparations that are inhaled or topically applied; massage with EO is included as an inhaled modality.; Exclude: Essential oil preparations that are ingested, consumed, or absorbed through oral and mucosal membranes. Also exclude preparations where essential oils are combined with another drug or active ingredient.
Comparators | No limits for comparators of inhaled-only EO interventions.; For EO-massage interventions, include only data from trials that had a massage-only comparator arm (eg, using an inert/carrier oil).
Outcomes | ▪ Psychological symptoms; ▪ Physical outcomes; ▪ Global outcomes (measures of quality of life or function, such as activities of daily living, mobility, social functioning, and employment); ▪ Harms
Timing | Any duration of treatment and follow-up
Study design | Systematic reviews and meta-analyses that include randomized controlled trials. Non-systematic reviews, reviews of reviews, and primary studies are excluded.
Setting | No limits

Potentially eligible SRs met all the following quality criteria: 1) clearly reported their search strategy and inclusion criteria; 2) performed a comprehensive search of at least 2 electronic databases; and 3) assessed the included studies for potential risk of bias and reported the findings.^15^

We identified the distinct health conditions and target populations that were examined by the potentially eligible SRs. When there were several qualified SRs of an intervention for the same health condition, we selected a single review to represent the evidence for that health condition or population, based on recentness, methodological quality, scope, and applicability.

## Data Abstraction

From each SR selected for the evidence map, we abstracted the following data: targeted health condition or population of the SR, intervention modalities and comparators used among eligible trials, number of RCTs and CCTs, sample size, and findings. Data were abstracted by 1 investigator and confirmed by at least 1 additional reviewer.

Some of the SRs selected for the evidence map examined a range of complementary therapies for a targeted health condition or included trials of EO interventions that we excluded from our scope, such as orally ingested formulations, or trials comparing EO-massage versus usual care. We abstracted data from trials that met our PICOTS criteria (Table 1).

We abstracted outcome data in 6 categories: psychological symptoms, nausea/vomiting, pain and other physical outcomes, global outcomes (specifically measures of functional status or quality of life), sleep quality, and adverse effects. If the effect sizes or P-values for the primary trials were not reported in the SR, we relied on the qualitative summary of findings provided by the SR authors.

## Quality Assessment

To qualify for inclusion in our evidence map, SRs were required to assess the methodological quality of RCTs using a standardized instrument, among other criteria.^15^ We took the adjudications made by the primary SR authors at face value and used their quality assessments to rate the overall body of evidence.

## Data Synthesis

We used the vector graphics in Microsoft Excel (2016) to generate scatter plots based on categorical values representing levels of effect and confidence in the evidence. The rows in the scatter plots present each of 26 health conditions/target populations. Each bubble represents the summary of findings for 1 of 5 outcome categories (psychological, nausea/vomiting, pain or other physical outcomes, global, and sleep). Because harms were infrequently reported, they are not represented in the evidence maps.

Two reviewers independently assessed the effectiveness of the interventions and confidence levels, based on data from eligible trials as reported in the systematic reviews. We resolved disagreements through discussion or by consulting a third reviewer until we reached consensus.

We classified the effect of the intervention for each targeted health condition and outcome as follows:

▪ No effect: a preponderance of null or negative findings.
▪ Unclear: the systematic review reported mixed findings for a single outcome, or mixed findings across multiple outcomes within the same category, with no preponderance of either benefit or negative effects.
▪ Potential positive effect: multiple outcomes within the same category (physical, psychological, global health, or sleep) with at least 1 clear finding of benefit; or mixed findings for a single outcome with a preponderance of evidence of a positive effect among RCTs.
▪ Positive effect: numerous studies or a large sample showing a positive effect.

For a modality to be classified as having a positive effect required consistent, statistically significant effects from well-conducted trials. When there were mixed findings for a single outcome that included both positive and null findings, we classified the overall effect as either unclear or potentially positive, depending on the preponderance of findings particularly among RCTs. If the findings across a group of studies were truly mixed to the extent that there was no preponderance of evidence in 1 direction or another, or if there were methodological limitations in the included trials, we classified it as unclear/insufficient. However, if there were a clear signal for benefit on at least 1 outcome in a category, we classified the overall body of evidence as having a potential positive effect.

We provide a narrative synthesis of findings according to treatment modality and outcome. Some SRs of inhaled EOs focused on a specific outcome such as nausea or sleep quality. Other SRs examined a specific health condition and reported multiple outcomes. We therefore compiled the findings for similar outcomes, grouping together psychological outcomes, nausea/vomiting, pain and other physical signs/symptoms, global outcomes, sleep quality, and adverse effects.

## Rating the Body of Evidence

For each conclusion on the effect of an intervention (ie, no effect, unclear, potential positive, or positive effect) we characterized the level of confidence in the body of evidence specific to that outcome category and health-related condition. We calculated a rough estimate of confidence based on the number of participants in the included trials; the number of studies; the quality of the included trials, and the overall risk of bias; whether there were serious inconsistencies in the findings; and any limitations in the applicability of the evidence (Appendix C). Table 2 outlines the criteria we used for scoring.

Table 2 Domains for assessing level of confidence

Domain; range of points | Description
Sample size;; 1 to 3 | 1: N ≤ 100; 2: N = 100–500; 3: N = 500+
Number of studies;; −1 or 0 | 0: More than 1 study; −1: Only 1 study
Consistency;; −1 or 0 | 0: No major flaw; −1: Serious inconsistency
Directness;; −1 or 0 | 0: No major flaw; −1: Limited applicability
Overall ROB/study quality;; −1 or 0 | 0: Unclear or low ROB (good quality); −1: High ROB (poor quality)

ROB = Risk of bias

We used the sum of points from each domain to classify the level of confidence into 4 categories as follows:

(3 points) | High: Consistent findings from at least 2 studies with a large combined sample size and low risk of bias.
(2 points) | Moderate: Evidence comes from a single large study with no major flaws, or from 2+ studies with limitations in sample size, study quality, applicability, or consistency of findings.
(1 point) | Low: Small combined sample size, or major deficiencies in the body of evidence.
(≤ 0 points) | Insufficient: The body of evidence consists of only 1 small study or has unacceptable deficiencies.

For the evidence maps, we grouped together studies with either unclear effect or insufficient level of confidence into a combined category of unclear/insufficient evidence.