# Introduction

The Veterans Health Administration (VHA) is seeking to increase the use of effective new practices and approaches in health care as part of its current transformation to a more patient-centered healthcare model that focuses on the Veterans’ goals and priorities for their health. The use of various low-risk complementary and alternative health interventions has been increasing both within and outside of the VHA.

Essential oils (EOs) are part of a tradition of herbal medicine dating back thousands of years.^2^ EOs are volatile oils that contain the “essence” of an aromatic plant’s fragrance. Conventional methods for extracting EOs include steam or water distillation from raw plant material,^3^ or cold-press extraction from citrus peel.^4^ The therapeutic inhalation of EOs is thought to have physiological and/or psychological benefits.^5^ Aromatherapy using EO is thought to mediate emotional responses by affecting the neuroendocrine system and autonomic nervous systems.^6^ In addition to the inhalation of EOs, there are various topical applications that are purported to be beneficial apart from their aromatic qualities, for instance as antiseptics. The chemical components of EOs have been shown to inhibit microbial and fungal growth.^7,8^

EO aromatherapy is being used increasingly in hospitals and other healthcare settings.^9,10^ For instance, aromatherapy has been used to help manage the behavioral and psychological symptoms of dementia, such as restlessness and aggression, and to improve sleep.^11^

Despite their increasing use, little is known about the benefits and risks associated with the use of EOs. The purpose of this report is to provide a broad overview, using evidence maps, of the health conditions and target populations for which EO interventions have been studied. Evidence maps are a relatively new form of evidence synthesis, and their purpose is to identify research gaps and future research needs, rather than to conduct comprehensive, in-depth analyses or form conclusions about a focused research question. Although standardized definitions and methodology are still being established, an evidence map generally includes a systematic search of a broad field of research and a visual representation of the body of literature.^12^ This report and evidence map characterize the current knowledge about the effectiveness of inhaled and topical EOs and will inform decision-making about these modalities in the VHA.