# Executive Summary

## Introduction

This topic was nominated by Dr. Ben Kligler, National Director of the Integrative Health Coordinating Center (IHCC) and Dr. Peter Glassman, Chair of the Medical Advisory Panel, Pharmacy Benefits Management Services at the Veterans Health Administration (VHA). The purpose of this report is to provide a broad overview of the effectiveness of aromatherapy and essential oils for various health indications. We will summarize the findings of systematic reviews in the form of evidence maps that will be used to guide and support decision-making about these treatment modalities in the VHA. The key question for the evidence map was: What evidence is available that examines the effectiveness of aromatherapy or essential oils for health-related indications?

## Methods

### Data Sources and Searches

We developed search strategies in consultation with a research librarian. We searched multiple data sources from database inception through February 2019 for systematic reviews (SRs) and meta-analyses of aromatherapy and essential oils.

### Study Selection

Two investigators independently assessed all abstracts and full-text articles for inclusion using pre-specified selection criteria and resolved disagreements through discussion and consensus. We included SRs and meta-analyses that included randomized controlled trials (RCTs) of clinical aromatherapy or topically applied essential oils (EOs) for specific health indications, risk populations, or targeted settings such as healthcare waiting spaces. From these SRs, we excluded results of trials in children, aromatherapy-massage trials without a massage-only control group, and trials that did not control for concurrent interventions. We excluded data from interventions in which EOs were applied to mucosal membranes, either orally, vaginally, or taken via ingestion.

Potentially eligible SRs met all the following quality criteria: 1) clearly reported their search strategy and inclusion criteria; 2) performed a comprehensive search of at least 2 electronic databases; and 3) assessed the included studies for potential risk of bias and reported the findings. When there were several qualified SRs of an intervention for the same health condition, we selected a single review to represent the evidence for that health condition or population, based on recentness, methodological quality, scope, and applicability.

### Data Abstraction

From each SR selected for the evidence map, we abstracted the following data: targeted health condition or population of the SR, intervention modalities and comparators used among trials, number of eligible RCTs and CCTs, sample size, and findings. Data were abstracted by 1 investigator and confirmed by at least 1 additional reviewer.

We abstracted outcome data in 6 categories: psychological symptoms, nausea/vomiting, pain and other physical outcomes, global outcomes (specifically measures of functional status or quality of life), sleep quality, and adverse effects. If the effect sizes or P-values for the primary trials were not reported in the SR, we relied on the qualitative summary of findings provided by the SR authors.

### Quality Assessment

To qualify for inclusion in our evidence map, SRs were required to assess the methodological quality of RCTs using a standardized instrument, among other criteria. We took the adjudications made by the primary SR authors at face value and used their quality assessments to rate the overall body of evidence.

### Data Synthesis and Rating the Body of Evidence

Using the vector graphics in Microsoft Excel (2016), we generated scatter plots representing the findings in 2 dimensions: level of effectiveness and confidence in the evidence. Two reviewers independently assessed the effectiveness of the interventions and confidence levels, based on data from eligible trials as reported in the systematic reviews. Each bubble represents the summary of findings for 1 of 5 outcome categories (psychological, nausea/vomiting, pain or other physical, global, and sleep). We did not include harms in the evidence map because they were seldom reported. See the figure below for the map of the evidence.

We classified the effect of the intervention for each health condition and outcome as follows:

▪ No effect: a preponderance of null or negative findings.
▪ Unclear: the systematic review reported mixed findings for a single outcome, or mixed findings across multiple outcomes within the same category, with no preponderance of either benefit or negative effects.
▪ Potential positive effect: multiple outcomes within the same category (pain/physical, nauseas/vomiting, psychological, global health, or sleep) with at least 1 clear finding of benefit; or mixed findings for a single outcome with a preponderance of evidence of a positive effect.
▪ Positive effect: numerous studies or a large sample showing a positive effect.

We classified the levels of confidence in the evidence as follows:

- High: Consistent findings from at least 2 studies with a large combined sample size and low risk of bias.
- Moderate: Evidence comes from a single large study with no major flaws, or from 2+ studies with limitations in sample size, study quality, applicability, or consistency of findings.
- Low: Small combined sample size, or major deficiencies in the body of evidence.
- Insufficient: The body of evidence consists of only 1 small study or has unacceptable deficiencies.

For the evidence maps, we grouped together studies with either unclear effect or insufficient level of confidence into a combined category of unclear/insufficient evidence. We also provide a narrative synthesis of findings according to treatment modality and outcome.

## Results

### Results of Literature Search

Our search of electronic databases, bibliographies, and other sources resulted in a total of 1,646 citations. After dual review of titles, abstracts, and full-text articles, we selected 25 SRs representing the most recent and comprehensive evidence available on each intervention, as applied to distinct health-related conditions and target populations.

### Summary of Results

Twenty-six health-related conditions/target populations were examined by the 25 SRs selected for the evidence map. Twenty-two SRs provide evidence on inhaled EO interventions, which encompass aromatherapy combined with massage (EO-massage) as well as inhaled-only aromatherapy. Three SRs provide evidence on topical EO interventions.

Evidence from 171 eligible trials is represented among the 25 SRs. Hemodialysis, perioperative patients, dysmenorrhea, labor/childbirth, sleep, anxiety, and depression were the most widely studied conditions and/or populations. Aromatherapy interventions were most commonly delivered via inhalation, though the method of application varied widely. SRs of aromatherapy frequently included trials of aromatherapy-massage, which may involve direct dermal exposure through the addition of EO to massage lotion or oil or may be diffused in the room during massage. There is moderate-confidence evidence that inhaled EOs are beneficial for pain in dysmenorrhea. Inhaled EOs have potential benefit for pain in labor/childbirth (moderate confidence) and for blood pressure reduction in patients with hypertension (low confidence). Two SRs provided low-confidence evidence of potential positive effects on sleep quality in various populations. There is moderate-confidence evidence that aromatherapy has no effect on anxiety in palliative care. The effects of inhaled EOs are unclear for nausea/vomiting in all studied populations, and for all other conditions studied. Among the topical EO interventions, there is evidence of potential effectiveness in the use of tea tree oil for tinea pedis and the level of confidence in the evidence is moderate. The effectiveness of topical EOs is unclear for onychomycosis, acne, and episiotomy wound healing.

Figure Map of the evidence from systematic reviews of inhaled and topical essential oils for targeted health conditions/populations

## Discussion

These evidence maps provide a broad overview of the evidence on clinical aromatherapy and topical EO interventions.

The only condition for which we found a preponderance of evidence suggesting benefit was pain in dysmenorrhea. We found several potentially promising areas, including pain in labor/childbirth; blood pressure reduction in those with hypertension; stress, depression, and sleep in patients on hemodialysis; stress in healthy adults; anxiety in perioperative patients undergoing various surgery types; and sleep quality in various populations. We also found evidence of potential effectiveness in the use of topical tea tree oil for tinea pedis. In most of the conditions studied, however, we found insufficient evidence to characterize treatment effects.

### Limitations

Evidence maps such as these are not designed to provide definitive conclusions about benefit, and there are several reasons for cautious interpretation: 1) we relied only on SRs and did not search for more recently published trials or conditions for which no SR has been written (so we cannot be definitive in our characterization of the evidence for each condition, nor is this an exhaustive list of conditions/populations for which aromatherapy has been used), 2) we cannot comment on the magnitude of treatment effect, 3) we relied on others’ study quality assessments, and 4) our measure of the level of confidence cannot approach the rigor represented by standardized approaches^1^ given the previously listed constraints. These maps provide only broad “brushstrokes” regarding the potential benefits of these interventions. One should be particularly circumspect about the “potential for positive effect” findings since these were – by design – weighted toward identifying any potential area of benefit to aid with research prioritization.

Similarly, evidence maps provide a broad overview about evidence gaps, but cannot be definitive in determining an absence of evidence. Data for these evidence maps came from systematic reviews; therefore, individual trials not included in prior reviews or areas for which there were no reviews meeting inclusion criteria are not represented in these evidence maps. It is possible that the maps have identified areas of insufficient evidence in which there is individual trial data, or systematic reviews that did not meet our minimum quality criteria.

### Research Gaps/Future Research

The maps highlight many potential areas for future research. The interventions and health conditions for which there was evidence of a “potential positive effect” may be one place to start to prioritize research, since these findings underscore potentially fruitful areas of research. The comparative effectiveness of different, standardized aromatherapeutic approaches should be examined especially in conditions for which there is potential promise. Future studies should capture potential adverse effects data, and the safety of aromatherapy should be examined in patients with comorbidities especially those of the respiratory tract. Furthermore, the use of a non-EO fragrance comparator would improve blinding and allow comparison of effects and harms of aromatherapy containing EO versus synthetically generated fragrance oils.

## Conclusions

There is moderate confidence that aromatherapy is effective for pain in dysmenorrhea. We found potential positive effects of aromatherapy for pain in labor/childbirth; blood pressure reduction in those with hypertension; stress, depression, and sleep in patients on hemodialysis; stress in healthy adults; anxiety in perioperative patients undergoing various surgery types; and sleep quality in various populations, with low to moderate confidence in the evidence. For EOs applied topically, there is moderate confidence in the potentially positive effect of tea tree oil for tinea pedis. There is insufficient evidence with which to determine whether aromatherapy or topically applied EO is effective for all other examined conditions.

## Abbreviations Table

Abbreviation: Term
ADL: Activities of daily living
AT: Aromatherapy
BPSD: Behavioral and Psychological Symptoms of Dementia
CCT: Controlled clinical trial
CDSR: Cochrane Database of Systematic Reviews
CI: Confidence interval
CIH: Complementary and integrative health
DBP: Diastolic blood pressure
EBM: Evidence-based Medicine
EO: Essential oil
EPDS: Edinburgh Postnatal Depression Scale
ESP: Evidence Synthesis Program
ICU: Intensive care unit
KQ: Key Question
MA: Meta-analysis
MADRS: Montgomery–Åsberg Depression Rating Scale
MD: Mean difference
MENQOL: Menopause-specific Quality of Life Questionnaire
NAS: Numeric analog scale
NOS: Not otherwise specified
NR: Not reported
NS: Not significant
OBO: Oil of bitter orange
OPCC&CT: Office of Patient Centered Care and Cultural Transformation
P: P-value
PBO: Placebo
PICOTS: Population, interventions, comparators, outcomes, timing, setting, and study design
pts: Participants
PUQE: Pregnancy-Unique Quantification of Emesis/Nausea
QOL: Quality of Life
RCSQ: Richards-Campbell Sleep Questionnaire
RCT: Randomized controlled trial
REEDA: Redness, Edema, Ecchymosis, Discharge, Approximation
ROB: Risk of bias
RR: Risk ratio
RSCL: Rotterdam Symptom Checklist
SBP: Systolic blood pressure
SE: Standard error
SMD: Standard mean difference
SR: Systematic review
STAI: State-Trait Anxiety Inventory
TEP: Technical expert panel
TMD: Total Mood Disturbance
TTO: Tea tree oil
US: United States
VAS: Visual analog scale
VHA: Veterans Health Administration