# APPENDIX D Peer Review Comments/Author Responses

Reviewer Number | Reviewer Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | Yes
2 | Yes
3 | Yes
4 | Yes
5 | Yes
7 | Yes
Is there any indication of bias in our synthesis of the evidence?
1 | No
2 | No
3 | Yes - The report states that it “included 25 SRs examining these interventions across a variety of targeted healthrelated conditions and populations” which one expects would mean that conditions as well as the population/s will be described.; However, the report goes onto describing “several potentially promising areas – including labor/childbirth, hypertension, hemodialysis, stress, perioperative care, and insomnia.” In this list, the report aggregates conditions and populations as if they were comparable items. For example, you may find a SR on labor/delivery population, but what you are really looking for is the effect of an intervention (i.e. aromatherapy) on a certain condition/symptom (i.e. anxiety) on a specific population (i.e. women undergoing labor/delivery). Therefore, the graphic provided as “map” reflects this same confusion regarding the evidence. For example, see Figure 1. Map of the evidence from systematic reviews of inhaled and topical essential oils for targeted health conditions/populations. In this figure, you see a list under the title “Inhaled EO Interventions” that includes: | We agree that the heterogeneity in the labels used for health condition/population categories presents a challenge. We have added a table to define the specific outcomes for each population, with additional notes about the study samples.; We have also relabeled the categories to specify symptoms or outcomes that were targeted by the intervention – for example, “SBP/DBP, hypertension” instead of simply “Hypertension” indicates that the condition treated was blood pressure, and not some other type of condition such as stress.
3 | [Continued from above] Anxiety in palliative care populations [this seems correct, it describes “Inhaled EO Interventions” on a certain condition/symptom (i.e. anxiety), on a specific population (i.e. palliative care patients) | Agree. No change was made.
3 | [Cont.] Burn patients - this seems to be missing information that would make the analysis helpful, as it describes “Inhaled EO Interventions” on a specific population (i.e. burn patients) but does not explain for what condition/symptom (i.e. anxiety). How is one supposed to understand the information? We know that the same intervention may have evidence for one symptom/condition, but not for another. | Replaced with “Symptom relief, burn patients”
3 | [Cont.] Cancer - Same as above, this seems to be missing information that would make the analysis helpful, as it describes “Inhaled EO Interventions” on a specific population (i.e. cancer patients) but does not explain for what condition/symptom (i.e. anxiety? Pain? Nausea?). How is one supposed to understand the information? I am having a hard time understanding what the information is that the report is conveying to a clinician who is trying to identify what to recommend to his/her patients asking if they could try aromatherapy for a certain symptom. | Replaced with “Symptom relief, cancer patients”
3 | [Cont.] Hemodialysis patients - Same as above, this seems to be missing information that would make the analysis helpful, as it describes “Inhaled EO Interventions” on a specific population (i.e. Hemodialysis patients) but does not explain for what condition/symptom (i.e. pruritus? Pain? fatigue?). when analyzing the literature, the evidence may be existing for some symptoms and not for others or may be of different quality for one symptom than another symptom. | We have relabeled the category to read, “Complications, hemodialysis patients”
3 | [Cont.] Similarly, in the conclusions, the report states: “There is moderate confidence that aromatherapy is effective for pain in dysmenorrhea. We found potential positive effects of aromatherapy for labor/childbirth [population missing condition/s], hypertension [[condition, missing population/s], hemodialysis [population missing condition/s], stress [condition, missing population/s], perioperative care [condition, missing population/s], and insomnia [condition, missing population/s], with low to moderate confidence in the evidence.”; According to the data abstraction paragraph in the report, this should be possible to do with the data abstracted. I also looked at the actual SRs on PubMed and all SRs included provide a list of the symptoms/conditions, so it is unclear why the report does not specify them (i.e. Bouya et al, 2018: The results showed that aromatherapy reduced some of the complications of hemodialysis, including anxiety, fatigue, pruritus, pain of arteriovenous fistula puncture, sleep quality, depression, stress and headache). | Agree, as above. We have more clearly noted the targeted conditions/symptoms and populations in Table 3.
4 | No
5 | No
7 | No
Are there any published or unpublished studies that we may have overlooked?
1 | No
2 | No
3 | No
4 | No
5 | Yes - Fismer and Pilkington (2012). Lavender and sleep. Europen J Integrative medicine.; Lakhan, Sheafer and Tepper (2016) Effectiveness of aromatherapy in reducing pain. Pain Research & Treatment. This systematic review may not have met all your criteria as I don’t see a rigorous review of risk of bias. | Thank you for bringing the Fismer review to our attention. It was not captured by our search. We have reviewed it, and all the studies it included (minus 1 dissertation by Borromeo) were also included in the more recent review by Lillehei and Halcon which is included in this evidence map.; The Lakhan review, while captured in our search, did not meet our criteria due to lack of ROB assessment.
7 | No
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report.
1
2 | Really excellent job | Thank you!
3 | it will be helpful to consistently report in the same format for all SRs, including the intervention, condition/symptom and population | Agree - we have relabeled the categories for greater consistency and added Table 3 to clarify the conditions/symptoms and populations.
4 | The report was complete and accurate within its scope. I assume that the criteria used are standard criteria for any health care intervention, but I wondered if other clinical intervention studies would normally have sample sizes of over 500 in order to be judged adequate. The authors were very clear about the limitations of the report given the paucity of systematic reviews. They also were clear that they did not evaluate the individual studies included in the reviews.; However, I would recommend in the future adding a column to the review tool addressing whether the SR authors addressed product integrity indicators (Latin name, chemotype, GC/MS analysis) in their review. | For the sample size criteria (500+), we combined samples from all trials that reported the outcome of interest.; The excellent suggestion to capture product integrity indicators is noted. Because we relied on evidence from systematic reviews rather than primary studies, product information was generally absent. We captured data about EO type and concentration when available, but even this information was sparsely reported.
5
7