# APPENDIX C Assessment of Confidence in the Evidence from Systematic Reviews of Aromatherapy and Essential Oils

Health condition/target population | Outcome category | Sample size; 1: <100; 2: 100–500; 3: 500+ | Number of trials; 0: 2+; −1: 1 | Consistency; 0: No major flaw; −1: Serious inconsistency | Directness; 0: No major flaw; −1: Limited applicability | Overall ROB; 0: Unclear or Low; −1: High | Confidence score | Summary of effect | Overall confidence
Inhaled EOs
Anxiety, healthcare waiting spaces^17^ | Psychological | 3 | 0 | −1 | 0 | 0 | 2^*^ | Unclear | Insufficient
Anxiety, palliative care^18^ | Psychological | 2 | 0 | 0 | 0 | −1 | 1 | No effect | Low
Anxiety, various populations^19^ | Psychological | 3 | 0 | −1 | −1 | −1 | 0 | Unclear | Insufficient
Burn patients^20^ | Psychological | 2 | 0 | −1 | 0 | −1 | 0 | Unclear | Insufficient
Burn patients^20^ | Physical | 2 | 0 | −1 | 0 | −1 | 0 | Unclear | Insufficient
Burn patients^20^ | Sleep | 1 | −1 | 0 | 0 | −1 | −1 | Unclear | Insufficient
Cancer ^21^ | Psychological | 2 | 0 | −1 | 0 | −1 | 0 | Unclear | Insufficient
Cancer ^21^ | Physical | 2 | 0 | −1 | 0 | −1 | 0 | Unclear | Insufficient
Cancer ^21^ | Global | 2 | 0 | −1 | 0 | −1 | 0 | Unclear | Insufficient
Dementia^16^ | Psychological | 2 | 0 | −1 | 0 | −1 | 0 | Unclear | Insufficient
Dementia^16^ | Global | 2 | 0 | −1 | 0 | 0 | 1^*^ | Unclear | Insufficient
Depression^22^ | Psychological | 3 | 0 | −1 | −1 | −1 | 0 | Unclear | Insufficient
Dysmenorrhea^23^ | Physical | 3 | 0 | −1 | 0 | 0 | 2 | Positive | Moderate
Hemodialysis patients^24^ | Psychological | 2 | 0 | −1 | 0 | 0 | 1 | Potential positive | Low
Hemodialysis patients^24^ | Physical | 2 | 0 | −1 | 0 | −1 | 0 | Unclear | Insufficient
Hemodialysis patients^24^ | Global | 1 | −1 | 0 | 0 | −1 | −1 | Unclear | Insufficient
Hemodialysis patients^24^ | Sleep | 2 | 0 | 0 | 0 | 0 | 2 | Potential positive | Moderate
Hypertension^25^ | Physical | 2 | 0 | −1 | 0 | 0 | 1 | Potential positive | Low
Labor/childbirth^26^ | Physical | 3 | 0 | −1 | 0 | 0 | 2 | Potential positive | Moderate
Nausea/vomiting, postoperative^27^ | Nausea/vomiting | 2 | 0 | −1 | 0 | −1 | 0 | Unclear | Insufficient
Nausea/vomiting, pregnancy^28^ | Psychological | 2 | −1 | 0 | 0 | 0 | 1^*^ | Unclear | Insufficient
Nausea/vomiting, pregnancy^28^ | Nausea/vomiting | 2 | 0 | 0 | 0 | 0 | 2^*^ | Unclear | Insufficient
Pain, hemiplegic shoulder pain after stroke^29^ | Physical | 1 | −1 | 0 | 0 | 0 | 0 | Unclear | Insufficient
Pain, postoperative ^30^ | Physical | 2 | 0 | −1 | 0 | −1 | 0 | Unclear | Insufficient
Perioperative, various surgery types^31^ | Psychological | 2 | 0 | 0 | 0 | −1 | 1 | Potential positive | Low
Perioperative, various surgery types^31^ | Physical | 2 | 0 | −1 | 0 | −1 | 0 | Unclear | Insufficient
Perioperative, various surgery types^31^ | Nausea/vomiting | 3 | 0 | −1 | 0 | −1 | 1^*^ | Unclear | Insufficient
Psychological symptoms in women aged 45+^32^ | Psychological | 2 | 0 | 0 | −1 | −1 | 0 | Unclear | Insufficient
Sexual symptoms in women aged 45+^33^ | Psychological | 1 | −1 | 0 | 0 | −1 | −1 | Unclear | Insufficient
Sleep, critical care/ICU^34^ | Sleep | 1 | −1 | 0 | 0 | −1 | −1 | Unclear | Insufficient
Sleep, various populations^35^ | Sleep | 2 | 0 | −1 | 0 | −1 | 1 | Potential positive | Low
Stress, healthy adults^36^ | Psychological | 2 | 0 | 0 | 0 | −1 | 1 | Potential positive | Low
Stress, nurses^37^ | Psychological | 2 | 0 | 0 | 0 | −1 | 1^*^ | Unclear | Insufficient
Topical EOs
Acne^38^ | Physical | 1 | −1 | 0 | 0 | 0 | 0 | Unclear | Insufficient
Episiotomy wound healing^39^ | Physical | 1 | −1 | 0 | 0 | 0 | 0 | Unclear | Insufficient
Onychomycosis^40^ | Physical | 2 | −1 | 0 | −1 | 0 | 0 | Unclear | Insufficient
Tinea pedis^40^ | Physical | 2 | 0 | 0 | 0 | 0 | 2 | Potential positive | Moderate

* Calculated confidence score was superseded by unclear treatment effect.