# APPENDIX B Study Selection

## Inclusion codes, code definitions, and criteria

1. Is the full-text of the article in English?
  - Yes → Proceed to 2.
  - No → STOP. Code X1 (Non-English language publication).
2. Does the population include adults (aged 18+) receiving an intervention of interest?
  - Yes → Proceed to 3.
  - No → STOP. Code X2 (Excluded population)
    Note: a study that includes both children and adults may be included if it represents the best or only evidence for a particular health condition.
3. Is the study design a systematic review or meta-analysis that includes randomized controlled trials (RCTs)?
  - Include: SR/MAs that conduct a comprehensive search (eg, more than one electronic database), specify inclusion/exclusion criteria, and assess study quality using validated criteria.
    Note: We will abstract data from controlled clinical trials (such as non-randomized controlled trials and pre-post experimental studies) that are included in the SR. The SR must include at least 1 RCT to be eligible for inclusion.
  - Exclude: Narrative or non-systematic review, critical review, scoping review, opinion/editorial, or primary study.
    - Yes → Proceed to 4.
    - No → STOP. Code X3 (Excluded study design or publication type)
    - B code instructions: Mark “B” any excludes that we should reference later, eg:
    - B-X3 – Narrative review with good background
    - B-X3 – May be useful for discussion
4. Does the systematic review include inhaled or topically applied essential oils among the interventions, and report results specific to essential oils? Studies of essential oils as an adjunct therapy that report the additional effects of the intervention, compared with a study arm containing the primary therapy by itself, are included.
  - Yes → Proceed to 5.
  - Include: essential oils produced by steam or water distillation of the leaves, wood, petals, buds, needles, bark, or roots of aromatic botanicals. In the case of citrus rind oils, cold-pressing is also an acceptable method of extraction.
  - Exclude: EO preparations that are ingested or directly applied to oral or mucosal membranes; aromatic oils not produced by steam or hydro distillation formulations that include active ingredients in addition to EOs, eg:
    - Vicks VapoRub (both regular and lemon versions contain camphor)
    - Evening primrose is not an EO, being cold-pressed from seed, however it may be used as a carrier oil in EO preparations. Epogam is a product derived from primrose.
    - Snoezelen, a multi-sensory intervention
  - No → STOP. Code X4 (Contains no EO data)
5. Code I (Systematic review that reports results specific to essential oils)
  Indicate the intervention type by recording the modality (eg, inhaled, topical, mouth rinse.) Also note the population or health condition, the specific essential oil if applicable, any other distinguishing characteristics.
  Example: “I – inhaled, dementia, tea tree oil”
6. If the systematic review is eligible but is superseded by a more recent, relevant, or comprehensive review on the same topic, use Code X6.