# APPENDIX A Search Strategies

Ovid MEDLINE(R) and Epub Ahead of Print, In-Process & Other Non-Indexed Citations and Daily 1946 to February 12, 2019

Date Searched: February 13, 2019

1 | Aromatherapy/ | 736
2 | (aromatherap* or aroma-therap* or “aroma oil*” or aromastick* or aromastick*).ti,ab,kf. | 1081
3 | or/1–2 | 1330
4 | Oils, Volatile/ or Plant Oils/ or Tea Tree Oil/ or (essential oil or essential oils or volatile oil or volatile oils).ti,ab,kf. | 34167
5 | (aroma* or aerosol* or alternative or balm* or bath* or CAM or caries or complementary or compress or compresses or cream or creams or dental or diffuse* or ENT or epicutaneous* or foam or foams or gel or gels or inhal* or integrative or liniment or liniments or lotion or lotions or mist* or mouth* or nasal or nose or odor or odors or odour or odours or “oil inhalation” or ointment* or olfactory or oral or orally or otorhinolaryngolog* or paste or pastes or patch or patches or periodontal or powder or powders or rinse* or spray* or spritzer* or scent* or skin or steam* or teeth or therap* or tincture or tinctures or tongue* or topical or topically or transdermal* or vapor or vapour).ti,ab,kf. | 5420778
6 | (ad or ch or pd or th or tu).fs. | 8556421
7 | or/5–6 | 11434051
8 | and/4,7 | 28181
9 | ((Allspice or Ambrette or Amyris or Angelica or Anise or Balsam or Basil or Bay or Beeswax or Benzoin or Bergamot or Birch or Boronia or “Bursera Graveolens” or Cade or Cajeput or Camphor or Cananga or Caraway or Cardamom or Carrot or Cassia or Catnip or Cedar or Cedarwood or Celery or Chamomile or Cilantro or Cinnamon or Cistus or Citronella or Citrus or Clove or Coffee or Coriander or Cornmint or Costus or Cubeb or Cumin or Cypress or Davana or Dill or Elemi or Eucalyptus or Fennel or Fir or Fragonia or Frankincense or Galbanum or Garlic or Geranium or Ginger or Grapefruit or Helichrysum or Hemlock or Hemp or Hinoki or Ho or “Hong Kuai” or Hops or Hyssop or Immortelle or Jasmine or Jatamansi or Juniper or Kanuka or Kunzea or Labdanum or Laurel or Lavandin or Lavender or Lemon or Lemongrass or Lime or Linden or Mandarin or Manuka or Marjoram or “May Chang” or Melissa or Menthol or Mint or Mugwort or Myrrh or Myrtle or Nard or Neroli or Niaouli or Nutmeg or Oakmoss or Olibanum or Opoponax or Orange or Oregano or Palmarosa or Palo-Santo or Parsley or Patchouli or Pepper or Peppermint or Petitgrain or Pimento or Pine or Primrose or Ravensara or Ravintsara or Rosalina or Rose or Rosemary or Rosewood or Sage or Sandalwood or Saro or Spearmint or Spikenard or Spruce or Tagetes or Tangerine or Tansy or Tea-Tree or Thuja or Thyme or Tobacco or Tuberose or Tulsi or Valerian or Vanilla or “Lemon Verbena” or Vetiver or Violet or Wintergreen or Wormwood or Yarrow or Ylang-Ylang or Yuzu) adj4 (oil or oils)).ti,ab,kf. | 8504
10 | ((Abelmoschus or Abies or Achillea or Agonis or Allium or Aloysia or Amyris or Anethum or Angelica or Aniba or Anthemis or Apis or Artemisia or Backhousia or Blumea or Boronia or Boswellia or Cananga or Callitris or Canarium or Carum or Cedrus or Chamaecyparis or Chamaemelum or Cinnamomum or Cistus or Coffea or Commiphora or Copaifera or Coriandrum or Croton or Cuminum or Cupressus or Cymbopogon or Daucus or Dipterocarpus or Elettaria or Eugenia or Evernia or Ferula or Foeniculum or Gaultheria or Helichrysum or Humulus or Hyssopus or Illicium or Jasminum or Juniperus or Kunzea or “Laurus Nobilis” or Lavendula or Lavandula or Leptospermum or Litsea or Matricaria or Melaleuca or Mentha or Myristica or Myroxylon or Myrtus or Nardostachys or Nepeta or Nicotania or Ocimum or Origanum or Pelargonium or Petroselinum or Picea or Pimenta or Pimento or Pimpinella or Pinus or Piper or Plectranthus or Pogostemon or Polianthes or Ravensara or Rosa or Rosmarinus or Salvia or Santalum or Schinus or Styrax or Syzygium or Tanacetum or Taxandria or Thymus or Tilia or Tsuga or Valeriana or Vetiveria or Viola or Zingiber) adj4 (oil or oils)).ti,ab,kf. | 5201
11 | (alphabisabolol or alpha-bisabolol or cineole or limonene or linalool or pinene or santanol).ti,ab,kf. | 7981
12 | or/9–11 | 18595
13 | and/7,12 | 15278
14 | or/3,8,13 | 35372
15 | Animals/ not Humans/ | 4514375
16 | 14 not 15 | 24794
17 | Systematic Reviews as Topic/ or Technology Assessment, Biomedical/ or Meta-Analysis as Topic/ or Review Literature as Topic/ | 33752
18 | (meta-analysis or systematic review).pt. | 157803
19 | (HTA* or “health technology assessment” or meta-anal* or metaanal* or ((evidence or rapid or systematic) adj3 (review* or synthesis or syntheses)) or search*).ti,ab,kf. | 556196
20 | or/17–19 | 581941
21 | and/16,20 | 753

Ovid PsycINFO 1806 to February Week 1 2019

Date searched: February 12, 2019

# | Searches | Results
1 | Aromatherapy/ | 141
2 | (aromatherap* or aroma-therap* or “aroma oil*” or aromastick* or aromastick*).ti,ab,id. | 248
3 | or/1–2 | 265
4 | “Medicinal Herbs and Plants”/ or (essential oil or essential oils or volatile oil or volatile oils).ti,ab,id. | 2144
5 | ((Allspice or Ambrette or Amyris or Angelica or Anise or Balsam or Basil or Bay or Beeswax or Benzoin or Bergamot or Birch or Boronia or “Bursera Graveolens” or Cade or Cajeput or Camphor or Cananga or Caraway or Cardamom or Carrot or Cassia or Catnip or Cedar or Cedarwood or Celery or Chamomile or Cilantro or Cinnamon or Cistus or Citronella or Citrus or Clove or Coffee or Coriander or Cornmint or Costus or Cubeb or Cumin or Cypress or Davana or Dill or Elemi or Eucalyptus or Fennel or Fir or Fragonia or Frankincense or Galbanum or Garlic or Geranium or Ginger or Grapefruit or Helichrysum or Hemlock or Hemp or Hinoki or Ho or “Hong Kuai” or Hops or Hyssop or Immortelle or Jasmine or Jatamansi or Juniper or Kanuka or Kunzea or Labdanum or Laurel or Lavandin or Lavender or Lemon or Lemongrass or Lime or Linden or Mandarin or Manuka or Marjoram or “May Chang” or Melissa or Menthol or Mint or Mugwort or Myrrh or Myrtle or Nard or Neroli or Niaouli or Nutmeg or Oakmoss or Olibanum or Opoponax or Orange or Oregano or Palmarosa or Palo-Santo or Parsley or Patchouli or Pepper or Peppermint or Petitgrain or Pimento or Pine or Primrose or Ravensara or Ravintsara or Rosalina or Rose or Rosemary or Rosewood or Sage or Sandalwood or Saro or Spearmint or Spikenard or Spruce or Tagetes or Tangerine or Tansy or Tea-Tree or Thuja or Thyme or Tobacco or Tuberose or Tulsi or Valerian or Vanilla or “Lemon Verbena” or Vetiver or Violet or Wintergreen or Wormwood or Yarrow or Ylang-Ylang or Yuzu) adj4 (oil or oils)).ti,ab. | 277
6 | ((Abelmoschus or Abies or Achillea or Agonis or Allium or Aloysia or Amyris or Anethum or Angelica or Aniba or Anthemis or Apis or Artemisia or Backhousia or Blumea or Boronia or Boswellia or Cananga or Callitris or Canarium or Carum or Cedrus or Chamaecyparis or Chamaemelum or Cinnamomum or Cistus or Coffea or Commiphora or Copaifera or Coriandrum or Croton or Cuminum or Cupressus or Cymbopogon or Daucus or Dipterocarpus or Elettaria or Eugenia or Evernia or Ferula or Foeniculum or Gaultheria or Helichrysum or Humulus or Hyssopus or Illicium or Jasminum or Juniperus or Kunzea or “Laurus Nobilis” or Lavendula or Lavandula or Leptospermum or Litsea or Matricaria or Melaleuca or Mentha or Myristica or Myroxylon or Myrtus or Nardostachys or Nepeta or Nicotania or Ocimum or Origanum or Pelargonium or Petroselinum or Picea or Pimenta or Pimento or Pimpinella or Pinus or Piper or Plectranthus or Pogostemon or Polianthes or Ravensara or Rosa or Rosmarinus or Salvia or Santalum or Schinus or Styrax or Syzygium or Tanacetum or Taxandria or Thymus or Tilia or Tsuga or Valeriana or Vetiveria or Viola or Zingiber) adj4 (oil or oils)).ti,ab. | 53
7 | (alphabisabolol or alpha-bisabolol or cineole or limonene or linalool or pinene or santanol).ti,ab. | 142
8 | or/4–7 | 2448
9 | (aroma* or aerosol* or alternative or balm* or bath* or CAM or caries or complementary or compress or compresses or cream or creams or dental or diffuse* or ENT or epicutaneous* or foam or foams or gel or gels or inhal* or integrative or liniment or liniments or lotion or lotions or mist* or mouth* or nasal or nose or odor or odors or odour or odours or “oil inhalation” or ointment* or olfactory or oral or orally or otorhinolaryngolog* or paste or pastes or patch or patches or periodontal or powder or powders or rinse* or spray* or spritzer* or scent* or skin or steam* or teeth or therap* or tincture or tinctures or tongue* or topical or topically or transdermal* or vapor or vapour).ti,ab,id. | 657880
10 | and/8–9 | 1229
11 | or/3,10 | 1379
12 | limit 11 to ("0830 systematic review" or 1200 meta analysis) | 53
13 | 11 and (HTA* or “health technology assessment” or meta-anal* or metaanal* or ((evidence or rapid or systematic) adj3 (review or synthesis)) or search*).ti,ab,id. | 120
14 | or/12–13 | 122

Ovid EBM Reviews - Cochrane Database of Systematic Reviews 2005 to February 6, 2019 and Health Technology Assessment 4th Quarter 2016

Date searched: February 13, 2019

[underlined: #] | Searches | Results
1 | (aromatherap* or aroma-therap* or “aroma oil*” or aromastick* or aroma-stick*).ti,ab. | 10
2 | (essential oil or essential oils or volatile oil or volatile oils).ti,ab. | 5
3 | ((Allspice or Ambrette or Amyris or Angelica or Anise or Balsam or Basil or Bay or Beeswax or Benzoin or Bergamot or Birch or Boronia or “Bursera Graveolens” or Cade or Cajeput or Camphor or Cananga or Caraway or Cardamom or Carrot or Cassia or Catnip or Cedar or Cedarwood or Celery or Chamomile or Cilantro or Cinnamon or Cistus or Citronella or Citrus or Clove or Coffee or Coriander or Cornmint or Costus or Cubeb or Cumin or Cypress or Davana or Dill or Elemi or Eucalyptus or Fennel or Fir or Fragonia or Frankincense or Galbanum or Garlic or Geranium or Ginger or Grapefruit or Helichrysum or Hemlock or Hemp or Hinoki or Ho or “Hong Kuai” or Hops or Hyssop or Immortelle or Jasmine or Jatamansi or Juniper or Kanuka or Kunzea or Labdanum or Laurel or Lavandin or Lavender or Lemon or Lemongrass or Lime or Linden or Mandarin or Manuka or Marjoram or “May Chang” or Melissa or Menthol or Mint or Mugwort or Myrrh or Myrtle or Nard or Neroli or Niaouli or Nutmeg or Oakmoss or Olibanum or Opoponax or Orange or Oregano or Palmarosa or Palo-Santo or Parsley or Patchouli or Pepper or Peppermint or Petitgrain or Pimento or Pine or Primrose or Ravensara or Ravintsara or Rosalina or Rose or Rosemary or Rosewood or Sage or Sandalwood or Saro or Spearmint or Spikenard or Spruce or Tagetes or Tangerine or Tansy or Tea-Tree or Thuja or Thyme or Tobacco or Tuberose or Tulsi or Valerian or Vanilla or “Lemon Verbena” or Vetiver or Violet or Wintergreen or Wormwood or Yarrow or Ylang-Ylang or Yuzu) adj4 (oil or oils)).ti,ab. | 11
4 | ((Abelmoschus or Abies or Achillea or Agonis or Allium or Aloysia or Amyris or Anethum or Angelica or Aniba or Anthemis or Apis or Artemisia or Backhousia or Blumea or Boronia or Boswellia or Cananga or Callitris or Canarium or Carum or Cedrus or Chamaecyparis or Chamaemelum or Cinnamomum or Cistus or Coffea or Commiphora or Copaifera or Coriandrum or Croton or Cuminum or Cupressus or Cymbopogon or Daucus or Dipterocarpus or Elettaria or Eugenia or Evernia or Ferula or Foeniculum or Gaultheria or Helichrysum or Humulus or Hyssopus or Illicium or Jasminum or Juniperus or Kunzea or “Laurus Nobilis” or Lavendula or Lavandula or Leptospermum or Litsea or Matricaria or Melaleuca or Mentha or Myristica or Myroxylon or Myrtus or Nardostachys or Nepeta or Nicotania or Ocimum or Origanum or Pelargonium or Petroselinum or Picea or Pimenta or Pimento or Pimpinella or Pinus or Piper or Plectranthus or Pogostemon or Polianthes or Ravensara or Rosa or Rosmarinus or Salvia or Santalum or Schinus or Styrax or Syzygium or Tanacetum or Taxandria or Thymus or Tilia or Tsuga or Valeriana or Vetiveria or Viola or Zingiber) adj4 (oil or oils)).ti,ab.0 | 0
5 | (alphabisabolol or alpha-bisabolol or cineole or limonene or linalool or pinene or santanol).ti,ab. | 0
6 | Or/1–5 | 23

EBSCOHost CINAHL

Date searched: February 19, 2019

# | Search | Results
S1 | (MH “Aromatherapy”) OR (MH “Aromatherapists”) | 1,997
S2 | TI ( aromatherap* or aroma-therap* or “aroma oil*” or aromastick* or aroma-stick* ) OR AB ( aromatherap* or aroma-therap* or “aroma oil*” or aromastick* or aroma-stick* ) | 1,203
S3 | S1 OR S2 | 2,278
S4 | (MH “Essential Oils+”) OR TI ( essential oil or essential oils or volatile oil or volatile oils ) OR AB ( essential oil or essential oils or volatile oil or volatile oils ) | 3,078
S5 | TI ( aroma* or aerosol* or alternative or balm* or bath* or CAM or caries or complementary or compress or compresses or cream or creams or dental or diffuse* or ENT or epicutaneous* or foam or foams or gel or gels or inhal* or integrative or liniment or liniments or lotion or lotions or mist* or mouth* or nasal or nose or odor or odors or odour or odours or “oil inhalation” or ointment* or olfactory or oral or orally or otorhinolaryngolog* or paste or pastes or patch or patches or periodontal or powder or powders or rinse* or spray* or spritzer* or scent* or skin or steam* or teeth or therap* or tincture or tinctures or tongue* or topical or topically or transdermal* or vapor or vapour ) OR AB ( aroma* or aerosol* or alternative or balm* or bath* or CAM or caries or complementary or compress or compresses or cream or creams or dental or diffuse* or ENT or epicutaneous* or foam or foams or gel or gels or inhal* or integrative or liniment or liniments or lotion or lotions or mist* or mouth* or nasal or nose or odor or odors or odour or odours or “oil inhalation” or ointment* or olfactory or oral or orally or otorhinolaryngolog* or paste or pastes or patch or patches or periodontal or powder or powders or rinse* or spray* or spritzer* or scent* or skin or steam* or teeth or therap* or tincture or tinctures or tongue* or topical or topically or transdermal* or vapor or vapour ) | 816,403
S6 | S4 AND S5 | 1,497
S7 | TI ( Allspice or Ambrette or Amyris or Angelica or Anise or Balsam or Basil or Bay or Beeswax or Benzoin or Bergamot or Birch or Boronia or “Bursera Graveolens” or Cade or Cajeput or Camphor or Cananga or Caraway or Cardamom or Carrot or Cassia or Catnip or Cedar or Cedarwood or Celery or Chamomile or Cilantro or Cinnamon or Cistus or Citronella or Citrus or Clove or Coffee or Coriander or Cornmint or Costus or Cubeb or Cumin or Cypress or Davana or Dill or Elemi or Eucalyptus or Fennel or Fir or Fragonia or Frankincense or Galbanum or Garlic or Geranium or Ginger or Grapefruit or Helichrysum or Hemlock or Hemp or Hinoki or Ho or “Hong Kuai” or Hops or Hyssop or Immortelle or Jasmine or Jatamansi or Juniper or Kanuka or Kunzea or Labdanum or Laurel or Lavandin or Lavender or Lemon or Lemongrass or Lime or Linden or Mandarin or Manuka or Marjoram or “May Chang” or Melissa or Menthol or Mint or Mugwort or Myrrh or Myrtle or Nard or Neroli or Niaouli or Nutmeg or Oakmoss or Olibanum or Opoponax or Orange or Oregano or Palmarosa or Palo-Santo or Parsley or Patchouli or Pepper or Peppermint or Petitgrain or Pimento or Pine or Primrose or Ravensara or Ravintsara or Rosalina or Rose or Rosemary or Rosewood or Sage or Sandalwood or Saro or Spearmint or Spikenard or Spruce or Tagetes or Tangerine or Tansy or Tea-Tree or Thuja or Thyme or Tobacco or Tuberose or Tulsi or Valerian or Vanilla or “Lemon Verbena” or Vetiver or Violet or Wintergreen or Wormwood or Yarrow or Ylang-Ylang or Yuzu) N4 (oil or oils) ) OR AB ( Allspice or Ambrette or Amyris or Angelica or Anise or Balsam or Basil or Bay or Beeswax or Benzoin or Bergamot or Birch or Boronia or “Bursera Graveolens” or Cade or Cajeput or Camphor or Cananga or Caraway or Cardamom or Carrot or Cassia or Catnip or Cedar or Cedarwood or Celery or Chamomile or Cilantro or Cinnamon or Cistus or Citronella or Citrus or Clove or Coffee or Coriander or Cornmint or Costus or Cubeb or Cumin or Cypress or Davana or Dill or Elemi or Eucalyptus or Fennel or Fir or Fragonia or Frankincense or Galbanum or Garlic or Geranium or Ginger or Grapefruit or Helichrysum or Hemlock or Hemp or Hinoki or Ho or “Hong Kuai” or Hops or Hyssop or Immortelle or Jasmine or Jatamansi or Juniper or Kanuka or Kunzea or Labdanum or Laurel or Lavandin or Lavender or Lemon or Lemongrass or Lime or Linden or Mandarin or Manuka or Marjoram or “May Chang” or Melissa or Menthol or Mint or Mugwort or Myrrh or Myrtle or Nard or Neroli or Niaouli or Nutmeg or Oakmoss or Olibanum or Opoponax or Orange or Oregano or Palmarosa or Palo-Santo or Parsley or Patchouli or Pepper or Peppermint or Petitgrain or Pimento or Pine or Primrose or Ravensara or Ravintsara or Rosalina or Rose or Rosemary or Rosewood or Sage or Sandalwood or Saro or Spearmint or Spikenard or Spruce or Tagetes or Tangerine or Tansy or Tea-Tree or Thuja or Thyme or Tobacco or Tuberose or Tulsi or Valerian or Vanilla or “Lemon Verbena” or Vetiver or Violet or Wintergreen or Wormwood or Yarrow or Ylang-Ylang or Yuzu) N4 (oil or oils) ) | 1,290
S8 | TI ( Abelmoschus or Abies or Achillea or Agonis or Allium or Aloysia or Amyris or Anethum or Angelica or Aniba or Anthemis or Apis or Artemisia or Backhousia or Blumea or Boronia or Boswellia or Cananga or Callitris or Canarium or Carum or Cedrus or Chamaecyparis or Chamaemelum or Cinnamomum or Cistus or Coffea or Commiphora or Copaifera or Coriandrum or Croton or Cuminum or Cupressus or Cymbopogon or Daucus or Dipterocarpus or Elettaria or Eugenia or Evernia or Ferula or Foeniculum or Gaultheria or Helichrysum or Humulus or Hyssopus or Illicium or Jasminum or Juniperus or Kunzea or “Laurus Nobilis” or Lavendula or Lavandula or Leptospermum or Litsea or Matricaria or Melaleuca or Mentha or Myristica or Myroxylon or Myrtus or Nardostachys or Nepeta or Nicotania or Ocimum or Oreganum or Origanum or Pelargonium or Petroselinum or Picea or Pimenta or Pimento or Pimpinella or Pinus or Piper or Plectranthus or Pogostemon or Polianthes or Ravensara or Rosa or Rosmarinus or Salvia or Santalum or Schinus or Styrax or Syzygium or Tanacetum or Taxandria or Thymus or Tilia or Tsuga or Valeriana or Vetiveria or Viola or Zingiber) N4 (oil or oils) ) OR AB ( Abelmoschus or Abies or Achillea or Agonis or Allium or Aloysia or Amyris or Anethum or Angelica or Aniba or Anthemis or Apis or Artemisia or Backhousia or Blumea or Boronia or Boswellia or Cananga or Callitris or Canarium or Carum or Cedrus or Chamaecyparis or Chamaemelum or Cinnamomum or Cistus or Coffea or Commiphora or Copaifera or Coriandrum or Croton or Cuminum or Cupressus or Cymbopogon or Daucus or Dipterocarpus or Elettaria or Eugenia or Evernia or Ferula or Foeniculum or Gaultheria or Helichrysum or Humulus or Hyssopus or Illicium or Jasminum or Juniperus or Kunzea or “Laurus Nobilis” or Lavendula or Lavandula or Leptospermum or Litsea or Matricaria or Melaleuca or Mentha or Myristica or Myroxylon or Myrtus or Nardostachys or Nepeta or Nicotania or Ocimum or Oreganum or Origanum or Pelargonium or Petroselinum or Picea or Pimenta or Pimento or Pimpinella or Pinus or Piper or Plectranthus or Pogostemon or Polianthes or Ravensara or Rosa or Rosmarinus or Salvia or Santalum or Schinus or Styrax or Syzygium or Tanacetum or Taxandria or Thymus or Tilia or Tsuga or Valeriana or Vetiveria or Viola or Zingiber) N4 (oil or oils) ) | 655
S9 | TI ( alphabisabolol or alpha-bisabolol or cineole or limonene or linalool or pinene or santanol ) OR AB ( alphabisabolol or alpha-bisabolol or cineole or limonene or linalool or pinene or santanol ) | 326
S10 | S7 OR S8 OR S9 | 1,923
S11 | S5 AND S10 | 1,000
S12 | S3 OR S6 OR S11 | 3,704
S13 | meta-analysis OR PT review OR PT systematic review OR TI ( HTA* or “health technology assessment” or meta-anal* or metaanal* or ((evidence or rapid or systematic) N3 (review* or synthesis or syntheses)) or search* ) OR AB ( HTA* or “health technology assessment" or meta-anal* or metaanal* or ((evidence or rapid or systematic) N3 (review* or synthesis or syntheses)) or search* ) | 396,037
S14 | S12 AND S13; Limiters - Exclude MEDLINE records | 184

PROSPERO

Date searched: February 20, 2019

(aromatherapy OR aroma-therapy OR “aroma oil” OR “aroma oils” or aromastick OR aromasticks OR aroma-stick OR aroma-sticks OR “essential oil” OR “essential oils” OR “volatile oil” OR “volatile oils” OR alphabisabolol OR alpha-bisabolol OR cineole OR limonene OR linalool OR pinene OR santanol OR ((Allspice OR Ambrette OR Amyris OR Angelica OR Anise OR Balsam OR Basil OR Bay OR Beeswax OR Benzoin OR Bergamot OR Birch OR Boronia OR “Bursera Graveolens” OR Cade OR Cajeput OR Camphor OR Cananga OR Caraway OR Cardamom OR Carrot OR Cassia OR Catnip OR Cedar OR Cedarwood OR Celery OR Chamomile OR Cilantro OR Cinnamon OR Cistus OR Citronella OR Citrus OR Clove OR Coffee OR Coriander OR Cornmint OR Costus OR Cubeb OR Cumin OR Cypress OR Davana OR Dill OR Elemi OR Eucalyptus OR Fennel OR Fir OR Fragonia OR Frankincense OR Galbanum OR Garlic OR Geranium OR Ginger OR Grapefruit OR Helichrysum OR Hemlock OR Hemp OR Hinoki OR Ho OR “Hong Kuai” OR Hops OR Hyssop OR Immortelle OR Jasmine OR Jatamansi OR Juniper OR Kanuka OR Kunzea OR Labdanum OR Laurel OR Lavandin OR Lavender OR Lemon OR Lemongrass OR Lime OR Linden OR Mandarin OR Manuka OR Marjoram OR “May Chang” OR Melissa OR Menthol OR Mint OR Mugwort OR Myrrh OR Myrtle OR Nard OR Neroli OR Niaouli OR Nutmeg OR Oakmoss OR Olibanum OR Opoponax OR Orange OR Oregano OR Palmarosa OR Palo-Santo OR Parsley OR Patchouli OR Pepper OR Peppermint OR Petitgrain OR Pimento OR Pine OR Primrose OR Ravensara OR Ravintsara OR Rosalina OR Rose OR Rosemary OR Rosewood OR Sage OR Sandalwood OR Saro OR Spearmint OR Spikenard OR Spruce OR Tagetes OR Tangerine OR Tansy OR Tea-Tree OR Thuja OR Thyme OR Tobacco OR Tuberose OR Tulsi OR Valerian OR Vanilla OR “Lemon Verbena” OR Vetiver OR Violet OR Wintergreen OR Wormwood OR Yarrow OR Ylang-Ylang OR Yuzu OR Abelmoschus OR Abies OR Achillea OR Agonis OR Allium OR Aloysia OR Amyris OR Anethum OR Angelica OR Aniba OR Anthemis OR Apis OR Artemisia OR Backhousia OR Blumea OR Boronia OR Boswellia OR Cananga OR Callitris OR Canarium OR Carum OR Cedrus OR Chamaecyparis OR Chamaemelum OR Cinnamomum OR Cistus OR Coffea OR Commiphora OR Copaifera OR Coriandrum OR Croton OR Cuminum OR Cupressus OR Cymbopogon OR Daucus OR Dipterocarpus OR Elettaria OR Eugenia OR Evernia OR Ferula OR Foeniculum OR Gaultheria OR Helichrysum OR Humulus OR Hyssopus OR Illicium OR Jasminum OR Juniperus OR Kunzea OR “Laurus Nobilis” OR Lavendula OR Lavandula OR Leptospermum OR Litsea OR Matricaria OR Melaleuca OR Mentha OR Myristica OR Myroxylon OR Myrtus OR Nardostachys OR Nepeta OR Nicotania OR Ocimum OR Origanum OR Pelargonium OR Petroselinum OR Picea OR Pimenta OR Pimento OR Pimpinella OR Pinus OR Piper OR Plectranthus OR Pogostemon OR Polianthes OR Ravensara OR Rosa OR Rosmarinus OR Salvia OR Santalum OR Schinus OR Styrax OR Syzygium OR Tanacetum OR Taxandria OR Thymus OR Tilia OR Tsuga OR Valeriana OR Vetiveria OR Viola OR Zingiber OR Abelmoschus OR Abies OR Achillea OR Agonis OR Allium OR Aloysia OR Amyris OR Anethum OR Angelica OR Aniba OR Anthemis OR Apis OR Artemisia OR Backhousia OR Blumea OR Boronia OR Boswellia OR Cananga OR Callitris OR Canarium OR Carum OR Cedrus OR Chamaecyparis OR Chamaemelum OR Cinnamomum OR Cistus OR Coffea OR Commiphora OR Copaifera OR Coriandrum OR Croton OR Cuminum OR Cupressus OR Cymbopogon OR Daucus OR Dipterocarpus OR Elettaria OR Eugenia OR Evernia or Ferula or Foeniculum or Gaultheria or Helichrysum or Humulus or Hyssopus or Illicium or Jasminum or Juniperus or Kunzea or “Laurus Nobilis” OR Lavendula OR Lavandula OR Leptospermum OR Litsea OR Matricaria OR Melaleuca OR Mentha OR Myristica OR Myroxylon OR Myrtus OR Nardostachys OR Nepeta OR Nicotania OR Ocimum OR Oreganum OR Origanum OR Pelargonium OR Petroselinum OR Picea OR Pimenta OR Pimento OR Pimpinella OR Pinus OR Piper OR Plectranthus OR Pogostemon OR Polianthes OR Ravensara OR Rosa OR Rosmarinus OR Salvia OR Santalum OR Schinus OR Styrax OR Syzygium OR Tanacetum OR Taxandria OR Thymus OR Tilia OR Tsuga OR Valeriana OR Vetiveria OR Viola) AND (oil or oils))) = 118 records

EPISTEMONIKOS

Date searched: February 20, 2019

title: (aromatherapy OR aroma-therapy OR “aroma oil” OR “aroma oils” or aromastick OR aromasticks OR aroma-stick OR aroma-sticks OR “essential oil” OR “essential oils” OR “volatile oil” OR “volatile oils” OR alphabisabolol OR alpha-bisabolol OR cineole OR limonene OR linalool OR pinene OR santanol) AND Publication Type = Systematic Review; OR; abstract: (aromatherapy OR aroma-therapy OR “aroma oil” OR “aroma oils” or aromastick OR aromasticks OR aroma-stick OR aroma-sticks OR “essential oil” OR “essential oils” OR “volatile oil” OR “volatile oils” OR alphabisabolol OR alpha-bisabolol OR cineole OR limonene OR linalool OR pinene OR santanol) AND Publication Type = Systematic Review; OR; title:(((Allspice OR Ambrette OR Amyris OR Angelica OR Anise OR Balsam OR Basil OR Bay OR Beeswax OR Benzoin OR Bergamot OR Birch OR Boronia OR “Bursera Graveolens” OR Cade OR Cajeput OR Camphor OR Cananga OR Caraway OR Cardamom OR Carrot OR Cassia OR Catnip OR Cedar OR Cedarwood OR Celery OR Chamomile OR Cilantro OR Cinnamon OR Cistus OR Citronella OR Citrus OR Clove OR Coffee OR Coriander OR Cornmint OR Costus OR Cubeb OR Cumin OR Cypress OR Davana OR Dill OR Elemi OR Eucalyptus OR Fennel OR Fir OR Fragonia OR Frankincense OR Galbanum OR Garlic OR Geranium OR Ginger OR Grapefruit OR Helichrysum OR Hemlock OR Hemp OR Hinoki OR Ho OR “Hong Kuai” OR Hops OR Hyssop OR Immortelle OR Jasmine OR Jatamansi OR Juniper OR Kanuka OR Kunzea OR Labdanum OR Laurel OR Lavandin OR Lavender OR Lemon OR Lemongrass OR Lime OR Linden OR Mandarin OR Manuka OR Marjoram OR “May Chang” OR Melissa OR Menthol OR Mint OR Mugwort OR Myrrh OR Myrtle OR Nard OR Neroli OR Niaouli OR Nutmeg OR Oakmoss OR Olibanum OR Opoponax OR Orange OR Oregano OR Palmarosa OR Palo-Santo OR Parsley OR Patchouli OR Pepper OR Peppermint OR Petitgrain OR Pimento OR Pine OR Primrose OR Ravensara OR Ravintsara OR Rosalina OR Rose OR Rosemary OR Rosewood OR Sage OR Sandalwood OR Saro OR Spearmint OR Spikenard OR Spruce OR Tagetes OR Tangerine OR Tansy OR Tea-Tree OR Thuja OR Thyme OR Tobacco OR Tuberose OR Tulsi OR Valerian OR Vanilla OR “Lemon Verbena” OR Vetiver OR Violet OR Wintergreen OR Wormwood OR Yarrow OR Ylang-Ylang OR Yuzu OR Abelmoschus OR Abies OR Achillea OR Agonis OR Allium OR Aloysia OR Amyris OR Anethum OR Angelica OR Aniba OR Anthemis OR Apis OR Artemisia OR Backhousia OR Blumea OR Boronia OR Boswellia OR Cananga OR Callitris OR Canarium OR Carum OR Cedrus OR Chamaecyparis OR Chamaemelum OR Cinnamomum OR Cistus OR Coffea OR Commiphora OR Copaifera OR Coriandrum OR Croton OR Cuminum OR Cupressus OR Cymbopogon OR Daucus OR Dipterocarpus OR Elettaria OR Eugenia OR Evernia OR Ferula OR Foeniculum OR Gaultheria OR Helichrysum OR Humulus OR Hyssopus OR Illicium OR Jasminum OR Juniperus OR Kunzea OR “Laurus Nobilis” OR Lavendula OR Lavandula OR Leptospermum OR Litsea OR Matricaria OR Melaleuca OR Mentha OR Myristica OR Myroxylon OR Myrtus OR Nardostachys OR Nepeta OR Nicotania OR Ocimum OR Origanum OR Pelargonium OR Petroselinum OR Picea OR Pimenta OR Pimento OR Pimpinella OR Pinus OR Piper OR Plectranthus OR Pogostemon OR Polianthes OR Ravensara OR Rosa OR Rosmarinus OR Salvia OR Santalum OR Schinus OR Styrax OR Syzygium OR Tanacetum OR Taxandria OR Thymus OR Tilia OR Tsuga OR Valeriana OR Vetiveria OR Viola OR Zingiber OR Abelmoschus OR Abies OR Achillea OR Agonis OR Allium OR Aloysia OR Amyris OR Anethum OR Angelica OR Aniba OR Anthemis OR Apis OR Artemisia OR Backhousia OR Blumea OR Boronia OR Boswellia OR Cananga OR Callitris OR Canarium OR Carum OR Cedrus OR Chamaecyparis OR Chamaemelum OR Cinnamomum OR Cistus OR Coffea OR Commiphora OR Copaifera OR Coriandrum OR Croton OR Cuminum OR Cupressus OR Cymbopogon OR Daucus OR Dipterocarpus OR Elettaria OR Eugenia OR Evernia OR Ferula OR Foeniculum OR Gaultheria OR Helichrysum OR Humulus OR Hyssopus OR Illicium OR Jasminum OR Juniperus OR Kunzea OR “Laurus Nobilis” OR Lavendula OR Lavandula OR Leptospermum OR Litsea OR Matricaria OR Melaleuca OR Mentha OR Myristica OR Myroxylon OR Myrtus OR Nardostachys OR Nepeta OR Nicotania OR Ocimum OR Oreganum OR Origanum OR Pelargonium OR Petroselinum OR Picea OR Pimenta OR Pimento OR Pimpinella OR Pinus OR Piper OR Plectranthus OR Pogostemon OR Polianthes OR Ravensara OR Rosa OR Rosmarinus OR Salvia OR Santalum OR Schinus OR Styrax OR Syzygium OR Tanacetum OR Taxandria OR Thymus OR Tilia OR Tsuga OR Valeriana OR Vetiveria OR Viola) AND (oil OR oils))) AND Publication Type = Systematic Review; OR; abstract:(((Allspice OR Ambrette OR Amyris OR Angelica OR Anise OR Balsam OR Basil OR Bay OR Beeswax OR Benzoin OR Bergamot OR Birch OR Boronia OR “Bursera Graveolens” OR Cade OR Cajeput OR Camphor OR Cananga OR Caraway OR Cardamom OR Carrot OR Cassia OR Catnip OR Cedar OR Cedarwood OR Celery OR Chamomile OR Cilantro OR Cinnamon OR Cistus OR Citronella OR Citrus OR Clove OR Coffee OR Coriander OR Cornmint OR Costus OR Cubeb OR Cumin OR Cypress OR Davana OR Dill OR Elemi OR Eucalyptus OR Fennel OR Fir OR Fragonia OR Frankincense OR Galbanum OR Garlic OR Geranium OR Ginger OR Grapefruit OR Helichrysum OR Hemlock OR Hemp OR Hinoki OR Ho OR “Hong Kuai” OR Hops OR Hyssop OR Immortelle OR Jasmine OR Jatamansi OR Juniper OR Kanuka OR Kunzea OR Labdanum OR Laurel OR Lavandin OR Lavender OR Lemon OR Lemongrass OR Lime OR Linden OR Mandarin OR Manuka OR Marjoram OR “May Chang” OR Melissa OR Menthol OR Mint OR Mugwort OR Myrrh OR Myrtle OR Nard OR Neroli OR Niaouli OR Nutmeg OR Oakmoss OR Olibanum OR Opoponax OR Orange OR Oregano OR Palmarosa OR Palo-Santo OR Parsley OR Patchouli OR Pepper OR Peppermint OR Petitgrain OR Pimento OR Pine OR Primrose OR Ravensara OR Ravintsara OR Rosalina OR Rose OR Rosemary OR Rosewood OR Sage OR Sandalwood OR Saro OR Spearmint OR Spikenard OR Spruce OR Tagetes OR Tangerine OR Tansy OR Tea-Tree OR Thuja OR Thyme OR Tobacco OR Tuberose OR Tulsi OR Valerian OR Vanilla OR “Lemon Verbena” OR Vetiver OR Violet OR Wintergreen OR Wormwood OR Yarrow OR Ylang-Ylang OR Yuzu OR Abelmoschus OR Abies OR Achillea OR Agonis OR Allium OR Aloysia OR Amyris OR Anethum OR Angelica OR Aniba OR Anthemis OR Apis OR Artemisia OR Backhousia OR Blumea OR Boronia OR Boswellia OR Cananga OR Callitris OR Canarium OR Carum OR Cedrus OR Chamaecyparis OR Chamaemelum OR Cinnamomum OR Cistus OR Coffea OR Commiphora OR Copaifera OR Coriandrum OR Croton OR Cuminum OR Cupressus OR Cymbopogon OR Daucus OR Dipterocarpus OR Elettaria OR Eugenia OR Evernia OR Ferula OR Foeniculum OR Gaultheria OR Helichrysum OR Humulus OR Hyssopus OR Illicium OR Jasminum OR Juniperus OR Kunzea OR “Laurus Nobilis” OR Lavendula OR Lavandula OR Leptospermum OR Litsea OR Matricaria OR Melaleuca OR Mentha OR Myristica OR Myroxylon OR Myrtus OR Nardostachys OR Nepeta OR Nicotania OR Ocimum OR Origanum OR Pelargonium OR Petroselinum OR Picea OR Pimenta OR Pimento OR Pimpinella OR Pinus OR Piper OR Plectranthus OR Pogostemon OR Polianthes OR Ravensara OR Rosa OR Rosmarinus OR Salvia OR Santalum OR Schinus OR Styrax OR Syzygium OR Tanacetum OR Taxandria OR Thymus OR Tilia OR Tsuga OR Valeriana OR Vetiveria OR Viola OR Zingiber OR Abelmoschus OR Abies OR Achillea OR Agonis OR Allium OR Aloysia OR Amyris OR Anethum OR Angelica OR Aniba OR Anthemis OR Apis OR Artemisia OR Backhousia OR Blumea OR Boronia OR Boswellia OR Cananga OR Callitris OR Canarium OR Carum OR Cedrus OR Chamaecyparis OR Chamaemelum OR Cinnamomum OR Cistus OR Coffea OR Commiphora OR Copaifera OR Coriandrum OR Croton OR Cuminum OR Cupressus OR Cymbopogon OR Daucus OR Dipterocarpus OR Elettaria OR Eugenia OR Evernia OR Ferula OR Foeniculum OR Gaultheria OR Helichrysum OR Humulus OR Hyssopus OR Illicium OR Jasminum OR Juniperus OR Kunzea OR “Laurus Nobilis” OR Lavendula OR Lavandula OR Leptospermum OR Litsea OR Matricaria OR Melaleuca OR Mentha OR Myristica OR Myroxylon OR Myrtus OR Nardostachys OR Nepeta OR Nicotania OR Ocimum OR Oreganum OR Origanum OR Pelargonium OR Petroselinum OR Picea OR Pimenta OR Pimento OR Pimpinella OR Pinus OR Piper OR Plectranthus OR Pogostemon OR Polianthes OR Ravensara OR Rosa OR Rosmarinus OR Salvia OR Santalum OR Schinus OR Styrax OR Syzygium OR Tanacetum OR Taxandria OR Thymus OR Tilia OR Tsuga OR Valeriana OR Vetiveria OR Viola) AND (oil OR oils))) AND Publication Type = Systematic Review; = 51 records