# REFERENCES

1 Desai NR, Bhatt DL. The state of periprocedural antiplatelet therapy after recent trials. JACC Cardiovasc Interv. Jun 2010;3(6):571–83. doi:10.1016/j.jcin.2010.04.008 20630450
2 Yousuf O, Bhatt DL. The evolution of antiplatelet therapy in cardiovascular disease. Nat Rev Cardiol. Jul 12 2011;8(10):547–59. doi:10.1038/nrcardio.2011.96 21750497
3 Steinhubl SR, Berger PB, Mann JT, 3rd, . Early and sustained dual oral antiplatelet therapy following percutaneous coronary intervention: a randomized controlled trial. JAMA. Nov 20 2002;288(19):2411–20. doi:10.1001/jama.288.19.2411 12435254
4 Yusuf S, Zhao F, Mehta SR, . Effects of clopidogrel in addition to aspirin in patients with acute coronary syndromes without ST-segment elevation. N Engl J Med. Aug 16 2001;345(7):494–502. doi:10.1056/NEJMoa010746 11519503
5 Bhatia K, Jain V, Aggarwal D, . Dual Antiplatelet Therapy Versus Aspirin in Patients With Stroke or Transient Ischemic Attack: Meta-Analysis of Randomized Controlled Trials. Stroke. Jun 2021;52(6):e217–e223. doi:10.1161/STROKEAHA.120.033033 33902301
6 Savonitto S, Caracciolo M, Cattaneo M, S DES. Management of patients with recently implanted coronary stents on dual antiplatelet therapy who need to undergo major surgery. J Thromb Haemost. Nov 2011;9(11):2133–42. doi:10.1111/j.1538-7836.2011.04456.x 21819537
7 Tokushige A, Shiomi H, Morimoto T, . Incidence and outcome of surgical procedures after coronary bare-metal and drug-eluting stent implantation: a report from the CREDO-Kyoto PCI/CABG registry cohort-2. Circ Cardiovasc Interv. Apr 2012;5(2):237–46. doi:10.1161/CIRCINTERVENTIONS.111.963728 22396582
8 Lawton JS, Tamis-Holland JE, Bangalore S, . 2021 ACC/AHA/SCAI Guideline for Coronary Artery Revascularization: A Report of the American College of Cardiology/American Heart Association Joint Committee on Clinical Practice Guidelines. Review. Circulation. 2022;145(3):E18–E114. doi:10.1161/CIR.0000000000001038 34882435
9 Valgimigli M, Bueno H, Byrne RA, . 2017 ESC focused update on dual antiplatelet therapy in coronary artery disease developed in collaboration with EACTS: The Task Force for dual antiplatelet therapy in coronary artery disease of the European Society of Cardiology (ESC) and of the European Association for Cardio-Thoracic Surgery (EACTS). Eur Heart J. Jan 14 2018;39(3):213–260. doi:10.1093/eurheartj/ehx419 28886622
10 Levine GN, Bates ER, Bittl JA, . 2016 ACC/AHA Guideline Focused Update on Duration of Dual Antiplatelet Therapy in Patients With Coronary Artery Disease: A Report of the American College of Cardiology/American Heart Association Task Force on Clinical Practice Guidelines. Circulation. Sep 6 2016;134(10):e123–55. doi:10.1161/cir.0000000000000404 27026020
11 Maggard Gibbons M, Ulloa JG, Macqueen IT, . Management of Antiplatelet Therapy Among Patients on Antiplatelet Therapy for Coronary or Cerebrovascular Disease or with Prior Percutaneous Cardiac Interventions Undergoing Elective Surgery: A Systematic Review. 2017. VA Evidence-based Synthesis Program Reports.
12 Childers CP, Mak S, Miake-Lye IM, . Management of Antiplatelet Therapy Among Patients on Antiplatelet Therapy for Cerebrovascular or Peripheral Vascular Diseases Undergoing Elective Non-Cardiac Surgery. 2017. VA Evidence-based Synthesis Program Reports.
13 Sterne JA, Hernan MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomised studies of interventions. BMJ. Oct 12 2016;355:i4919. doi:10.1136/bmj.i4919 27733354
14 The Grading of Recommendations Assessment Development and Evalution. https://www.gradeworkinggroup.org/
15 Tarrant SM, Kim RG, McGregor KL, Palazzi K, Attia J, Balogh ZJ. Dual Antiplatelet Therapy and Surgical Timing in Geriatric Hip Fracture. J Orthop Trauma. Oct 2020;34(10):559–565. doi:10.1097/bot.0000000000001779 32304474
16 Kremke M, Gissel MS, Jensen MJ, Thomassen SA, Jakobsen CJ. The association between a three-day ticagrelor discontinuation and perioperative bleeding complications. Eur J Cardiothorac Surg. Apr 1 2019;55(4):714–720. doi:10.1093/ejcts/ezy355 30358828
17 Nardi P, Pisano C, Turturici M, . The impact of dual antiplatelet therapy administration on the risk of bleeding complications during coronary artery bypass surgery. Kardiochir Torakochirurgia Pol. Sep 2021;18(3):145–151. doi:10.5114/kitp.2021.109407 34703471
18 Della Corte A, Bancone C, Spadafora A, . Postoperative bleeding in coronary artery bypass patients on double antiplatelet therapy: predictive value of preoperative aggregometry. Eur J Cardiothorac Surg. Nov 1 2017;52(5):901–908. doi:10.1093/ejcts/ezx181 28977378
19 Kacar SM, Mikic A, Kačar MB. Postoperative Bleeding Following Preoperative Clopidogrel Administration in Patients with Haemoglobin Level Above 110 g/L Undergoing Urgent CABG. Braz J Cardiovasc Surg. Jan–Feb 2018;33(1):59–63. doi:10.21470/1678-9741-2017-0083 29617503
20 Shahid M, Islam MU, Ahmad I, . Post operative complications associated with preoperative use of clopidogrel in patients undergoning coronary artery bypass surgery. Article. Pakistan Journal of Medical and Health Sciences. 2021;15(10):3154–3156. doi:10.53350/pjmhs2115103154
21 Heidari A, Dezfouli FG, Tabatabi K, . Combined clopidogrel and aspirin treatment up to surgery dosen’t increase the risk of postoperative blood loss and reoperation for bleeding in patients undergoing coronary artery bypass grafting. Article. International Journal of Pharmaceutical Research and Allied Sciences. 2016;5(3):164–167.
22 Irie H, Kawai K, Otake T, Shinjo Y, Kuriyama A, Yamashita S. Outcomes of patients on dual antiplatelet therapy post-coronary stenting following emergency noncardiac surgery. Acta Anaesthesiol Scand. Sep 2019;63(8):982–992. doi:10.1111/aas.13377 31020653
23 Cao D, Levin MA, Sartori S, . Perioperative risk and antiplatelet management in patients undergoing non-cardiac surgery within 1 year of PCI. Article. Journal of Thrombosis and Thrombolysis. 2022;53(2):380–389. doi:10.1007/s11239-021-02539-8 34386899
24 Kim C, Kim JS, Kim H, . Patterns of antiplatelet therapy during noncardiac surgery in patients with second-generation drug-eluting stents. Article. Journal of the American Heart Association. 2020;9(11)doi:10.1161/JAHA.119.016218
25 Doğan A, Özdemir E, Kahraman S, Açıl T, Saltan Y, Kurtoğlu N. Impact of early (3 months) dual antiplatelet treatment interruption prior to renal transplantation in patients with second-generation DES on perioperative stent thrombosis and MACEs. Anatol J Cardiol. Dec 2017;18(6):391–396. doi:10.14744/AnatolJCardiol.2017.7885 29256873
26 Douketis JD, Spyropoulos AC, Murad MH, . Perioperative Management of Antithrombotic Therapy: An American College of Chest Physicians Clinical Practice Guideline. Chest. Nov 2022;162(5):e207–e243. doi:10.1016/j.chest.2022.07.025 35964704
27 Cheng Y, Liu X, Zhao Y, . Risk Factors for Postoperative Events in Patients on Antiplatelet Therapy Undergoing Off-Pump Coronary Artery Bypass Grafting Surgery. Angiology. Sep 2020;71(8):704–712. doi:10.1177/0003319720919319 32295386
28 De Servi S, Morici N, Boschetti E, . Bridge therapy or standard treatment for urgent surgery after coronary stent implantation: Analysis of 314 patients. Vascul Pharmacol. May 2016;80:85–90. doi:10.1016/j.vph.2015.11.085 26657879
29 Gielen CL, Bruggemans EF, Stijnen T, . Stopping antiplatelet medication before coronary artery bypass graft surgery: is there an optimal timing to minimize bleeding? Comparative Study; Journal Article; Randomized Controlled Trial; Research Support, Non-U.S. Gov’t. European journal of cardio-thoracic surgery. 2015;48(4):e64–70. doi:10.1093/ejcts/ezv269 26248820
30 Hansson EC, Jidéus L, Åberg B, . Coronary artery bypass grafting-related bleeding complications in patients treated with ticagrelor or clopidogrel: a nationwide study. Eur Heart J. Jan 7 2016;37(2):189–97. doi:10.1093/eurheartj/ehv381 26330426
31 Kapoor S, Singh G, Arya RC, . Effect of anti-platelet therapy on peri-operative blood loss in patients undergoing off-pump coronary artery bypass grafting. Article. Annals of Cardiac Anaesthesia. 2022;25(2):182–187. doi:10.4103/aca.aca_12_22 35417965
32 Vuilliomenet T, Gebhard C, Bizzozero C, . Discontinuation of dual antiplatelet therapy and bleeding in intensive care in patients undergoing urgent coronary artery bypass grafting: a retrospective analysis. Interact Cardiovasc Thorac Surg. May 1 2019;28(5):665–673. doi:10.1093/icvts/ivy330 30535154
33 Murray M, Sundin D, Cope V. Supporting new graduate registered nurse transition for safety: A literature review update. Collegian. 2020;27(1):125–134. doi:10.1016/j.colegn.2019.04.007
34 Altun G, Hemşinli D, Pulathan Z, Civelek A. Emergency coronary bypass surgery in patients under the influence of dualantiplatelet therapy: effects of tranexamic acid and desmopressin acetate. Turk J Med Sci. Dec 19 2017;47(6)doi:10.3906/sag-1612-140