# ACKNOWLEDGMENTS

The authors are grateful to the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Jason M. Johanning, MD, MS
  Medical Director
  Surgical Quality Improvement Program, National Surgery Office

## Technical Expert Panel

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Benjamin Brooke, MD, PhD, FACS, DFSVS
  Chief, Division of Vascular Surgery
  Associate Professor of Surgery
  Adjunct Associate Professor of Bioinformatics & Population Health Sciences
  Section Chief, Health Services Research
  University of Utah
- Augustus (Rob) Hough, PharmD, BCPS, BCCP
  Clinical Pharmacy Specialist – Cardiology
  PGY2 Cardiology Pharmacy Residency Director
  VA Medical Center, West Palm Beach, FL
- Sunil Rao, MD
  Professor of Medicine and Director of Interventional Cardiology
  New York University Langone Health

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence (see Appendix F for disposition of comments). Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center works to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.