# DISCUSSION

Perhaps the most important finding from this review is how little evidence is available for this consequential decision made many times every day at surgical centers around the country. We identified no RCTs, meaning all the evidence comes from observational studies with methodologic limitations, chiefly the concern for confounding in the patient selection for the different DAPT strategies. The strongest signal we could find, which was still low certainty evidence, was that the suspension of DAPT therapy greater than 2 days was associated with less bleeding, transfusions, and re-explorations, and limited to patients undergoing CABG. Data about other surgical procedures, other DAPT strategies, patients with non-cardiac stents, and other outcomes were either so limited that no conclusions could be drawn, or absent entirely. In particular, although we found a signal that suspending DAPT therapy for 3 days or greater was associated with less bleeding in CABG surgery, the clinical significance of this blood loss is uncertain, as the quantity of average blood loss across DAPT strategies amounted to <300 mL of blood. We were unable to find any conclusive evidence about that strategy’s association with cardiac outcomes. Without this information, it is difficult to determine whether risks of suspending DAPT therapy outweigh its benefits.

Acknowledging these limitations, our findings pertaining to the possible benefits of holding DAPT greater than 2 days prior to CABG in terms of reduced bleeding risk are consistent with the 2021 ACC/AHA/SCAI guidelines for coronary artery revascularization and the 2017 European guidelines for dual antiplatelet therapy that recommend continuing aspirin perioperatively but holding clopidogrel for 5 days, ticagrelor for 3 days, and prasugrel for 7 days prior to elective CABG.^8,9^ In our review, we considered DAPT discontinuation or withholding as stopping 1 or both antiplatelet agents, which most often entailed holding the P2Y12 agent. Similar DAPT advice is provided for non-cardiac surgery in the 2022 Chest guidelines, and the same preoperative P2Y12 withholding periods are also endorsed in current prescribing information from Sanofi-Aventis, AstraZeneca, and Eli Lily for clopidogrel, ticagrelor, and prasugrel, respectively.^26^

## LIMITATIONS

This systematic review was limited by the quality of available evidence pertaining to the topic of antiplatelet management in the perioperative period. Had we limited our inclusion criteria to only RCTs, we would have been left without studies that addressed the key questions and met inclusion criteria. Thus, we needed to include observational studies, but doing so brings its own set of limitations. The majority of included observational studies were single-center experiences, and the attempts to control for confounding were uneven. Thus, our report includes no studies at low risk of bias.

Further hampering our ability to make cross-study comparisons was the inconsistency in comparison groups and reported outcomes. There was a wide range of observed antiplatelet strategies that included holding 1 or both agents for variable amounts of time preoperatively, bridging with intravenous antiplatelet medications, or using an entirely different medication or technique to prevent adverse bleeding outcomes. We attempt to summarize some of the data from CABG studies in the figures, with the caveat that, in dichotomizing the strategies as DAPT withdrawal for > or ≤2 days, some studies with prolonged DAPT withholding (ie, 7 days or more) are included in the >2 days withdrawal and may be skewing the results. We also recognize that there are significant differences in the pharmacokinetic and pharmacodynamic profiles of available P2Y12 inhibitors, and that grouping them together risks oversimplifying any conclusions drawn from this review.

While some clinical outcomes such as reoperation and mortality were used by several studies, composite cardiovascular outcomes, such as MACE, and standardized bleeding outcomes were particularly disparate among the studies. For example, few studies used standardized bleeding outcomes such as BARC definitions, and instead we found a variety of reported lab values, quantities of transfused blood products, or blood loss at arbitrary postoperative time points.

Furthermore, nearly all the available data are about patients with stents (mostly cardiac stents) on preoperative DAPT who are undergoing CABG. This accounted for about 75% of included studies. No studies reported limb outcomes, such as MALE. Thus, the hypothetical case in the VA setting for which evidence was needed—that of a patient on DAPT for a lower limb stent who was now undergoing a renal operation—has no evidence available to inform the decision.

Lastly, there is always the issue of generalizability from the context of the published study to the clinical context where DAPT decisions must be made.

## FUTURE RESEARCH

Clearly this field needs much future research. Such research should use well-established measures for both benefits (standardized measures of bleeding, such as BARC) and risks (standardized measures of cardiac events, such as MACE, or limb events, such as MALE). This will facilitate the comparison of results across studies, which was a major challenge with this review. Additionally, given the unique pharmacokinetic and pharmacodynamic properties of available P2Y12 agents, further research would ideally be able to yield recommendations for specific antiplatelet agents.

The best way to provide high-quality evidence on this topic would be with 1 or more well-designed RCTs, but such studies are challenging to mount, are resource intensive, and often do not yield conclusive findings for many years. Observational studies are appealing because they can be accomplished in less time and with fewer resources, but it is clear from the studies we found that better observational studies are needed. These studies should: 1) include data on potential confounders to facilitate risk adjustment; 2) use a sample large enough to provide sufficient statistical power for subgroup analyses like those posed in Key Question 2; 3) periodically audit the accuracy of data so that researchers can have confidence in the variables and values in the dataset; 4) employ data from multiple institutions and surgical teams to reduce the impact of site and surgical team effects that could obscure the effect of DAPT strategy choice; and 5) analyze and report outcomes as standardized composite endpoints such as BARC and MACE. The obvious possibility for a dataset that is sufficiently large and informative, and directly relevant to subjects and clinical practice within VA, is the VA Surgical Quality Improvement Program (QUIP) database. It would be worth an exploratory assessment of whether there is sufficient variation in DAPT strategies among patients in the VA QUIP database to allow for an analysis like the one outlined above. If the VA QUIP data are unable to provide clinically useful conclusions regarding the above questions, then the VA Corporate Data Warehouse (CDW) could evaluated as another potential data source for an adequately powered epidemiologic analysis, although there will need to be more preparatory work if using CDW data than if using data from VA QUIP.

## CONCLUSIONS

The evidence base on the benefits and risks of different perioperative DAPT strategies for patient with stents is extremely thin. The strongest signal, which was still based on low certainty evidence, is that suspension of DAPT for greater than 2 days prior to CABG surgery is associated with less bleeding, transfusions, and re-explorations. Different DAPT strategies’ association with other outcomes of interest, such as MACE, remains uncertain.