# RESULTS

## LITERATURE FLOW

The literature flow diagram (Figure 1) summarizes the results of the study selection process (full list of excluded studies available in Appendix B).

Figure 1 Literature Flowchart

## LITERATURE OVERVIEW

The literature search identified 3,565 potentially relevant citations, 509 of which were included at the abstract screening level. From these, a total of 443 abstracts were excluded for the following reasons: no comparison of patients on preoperative DAPT with at least 2 alternative preoperative or postoperative management groups (N = 108), study design (N = 104), not about major surgery for which postoperative DAPT would be expected (N = 76), other reasons (N = 57), patients are not on preoperative DAPT (N = 52), background (N = 36), and postoperative outcomes not included (N = 10). This left 66 publications for full-text review, of which 48 publications were excluded for the following reasons: no relevant outcome data presented for the patients that were on preoperative DAPT comparing at least 2 perioperative strategies (N = 38), endovascular (N = 3), transcatheter aortic valve replacement (TAVR) (N = 1), DAPT interruption is not specified (N = 1), does not specify dual antiplatelet (N = 1), no outcome of interest (N = 1), not at least 2 comparison groups of patients on DAPT (N = 1), single arm with bridging (N = 1), and unavailable (N = 1). A full list of excluded studies from the full-text review is in Appendix B. A total of 18 publications were identified at full-text review as meeting initial inclusion criteria. Details of included publications are available in Appendix E.

## DESCRIPTION OF THE EVIDENCE

We identified 18 publications that met the inclusion criteria. Of these 18 observational studies, 2^15,16^ were propensity matched for patient and surgery characteristics (such as age, sex, comorbidities, severity of surgical disease, and surgical approach). Most studies were single-institution designs (N = 14). The majority of studies evaluated DAPT management at the time of CABG (N = 12), 3 studies evaluated varied groups of non-cardiac operations, and 1 study combined cardiac and non-cardiac surgery. Lastly, there was 1 study each evaluating hip fracture surgery and renal transplant outcomes. The strategies for perioperative management of DAPT varied: the most common approach compared different durations of time between stopping an antiplatelet agent and surgery (N = 11). Other comparisons included discontinuing 1 or both antiplatelet agents compared to continuing. One study compared a P2Y12 inhibitor discontinuation with IV tirofiban infusion (N = 1).

### Risk of Bias

For the 18 observational studies, the quality of the studies was variable. Only 1 study was at low risk of confounding and the remainder were at medium or high risk. While most studies included a consecutive or full sample of patients from the specified operations, several did not and were considered moderate risk for selection bias (N = 10). There was overall low risk of bias in the classification of the interventions and deviation from these intended interventions (we judged retrospective chart review of drugs a patient received and the surgical procedure to be accurate). Missing data was not considered a significant source of bias given the use of retrospective chart reviews as the data source and the short term (perioperative) outcomes of most studies. Finally, several studies were at moderate or high risk of measurement bias, usually due to using unvalidated or non-standard measures of bleeding outcomes (N = 8). Several studies did not report cardiovascular outcomes and did provide a rationale for why clinically useful outcomes were not included. We felt that these may be at risk for reporting biases (N = 7).

## KEY QUESTION 1 AMONG ADULTS ON DUAL ANTIPLATELET THERAPY (DAPT) UNDERGOING MAJOR ELECTIVE, URGENT, OR EMERGENT SURGERIES, WHAT IS THE OCCURRENCE OF MAJOR ADVERSE EVENTS WHEN DAPT IS CONTINUED VERSUS SUSPENDED OR VARIED PERIOPERATIVELY?

Our search identified 18 studies that met eligibility criteria. In these studies, dual antiplatelet therapy was defined as aspirin plus a P2Y12 inhibitor, often clopidogrel or an unspecified agent. Among these, 12 were studies about DAPT management in coronary artery bypass surgery (CABG), 3 were studies involving non-cardiac surgery, 1 included both cardiac and non-cardiac surgery, 1 specifically included just hip operations, and 1 was only inclusive of renal transplant surgery. All included studies were observational; the majority were conducted at single centers, while 5 included patients from multiple institutions. Given the predominance of observational studies involving CABG, we present the results of these studies together in the following figures when possible. The others are discussed separately below.

### Patients on Preoperative DAPT and Undergoing CABG

#### Bleeding Outcomes

##### Blood loss

Eleven observational CABG studies contained sufficient data on postoperative blood loss to be presented collectively in Figure 2. Of these, 8 compared suspending DAPT (defined as holding P2Y12 inhibition with continuation of acetylsalicylic acid [ASA]) at various preoperative timepoints, which we dichotomized as ≤2 days withdrawal or >2 days withdrawal. Of note, 1 study that grouped 48–72 hours was placed in the >2 days withdrawal group.^17^ A second study had comparison groups of 0–3 days and >4 days, which were reassigned to ≤2 and >2 withdrawal days, respectively.^18^ The remaining 3 studies compared holding DAPT to continuing DAPT until surgery. In 6 of the 11 studies shown in Figure 2, mean blood loss was statistically lower in patients that either experienced withdrawal of DAPT >2 days preop or discontinuation of DAPT. The other 5 studies showed no significant differences in mean blood loss between DAPT management groups. Only 2 studies^19,20^ reported higher blood loss in the DAPT-withheld or discontinued groups; however, these differences were minimal (≤30 mL) and nonsignificant. Longer duration of suspension of DAPT therapy (ie, for more than 2 days) favored less blood loss. However, while these studies demonstrated a statistically significant difference in postoperative blood loss between DAPT management strategies, the clinical significance of blood loss of this size (<300 mL) is uncertain.

Figure 2 Blood Loss Outcomes

#### Transfusions

Differences in red blood cell transfusion requirements across DAPT strategies from the 9 observational CABG articles that reported transfusion outcomes are shown in Figure 3. Of the 9 available studies, 4 showed less transfusion requirements for >2 days DAPT withdrawal or discontinuing DAPT, 4 reported nonsignificant results (3 of which favored >2 days DAPT withdrawal or discontinuation), and only 1 study^21^ reported statistically more transfusions in the DAPT discontinuation group.

Figure 3 Transfusions Outcomes

#### Re-explorations

Surgical re-exploration data showed a similar pattern, with all the point estimates favoring less re-exploration in patients with >2 days DAPT withdrawal (in 2 of 5 studies this difference was not statistically significant). In contrast, the 2 studies of DAPT discontinuation found no difference in re-exploration (Figure 4).

Figure 4 Re-exploration Outcomes

#### Perioperative Death

There were 4 observational CABG studies that reported mortality risk differences across comparison arms (shown in Figure 5) and 1 additional study^17^ that reported mortality as odds ratios. None of these reported significant differences in patient death across DAPT management strategies.

Figure 5 Perioperative Death Outcomes

#### Cardiac Outcomes

There were too few CABG studies that reported similar cardiac outcomes to graph. Nardi and colleagues^17^ observed no incidences of myocardial infarction for all DAPT management strategies, which included holding P2Y12 inhibition for 0 to 4 days prior to CABG. In a multicenter observational study of patients undergoing isolated CABG, Gielen et al found no significant association between last use of DAPT and MACE (odds ratio [OR] = 0.849, 95% CI [0.635, 1.135], P = 0.27).

### Patients on Preoperative DAPT and Undergoing Non-cardiac Surgery

Three studies reported outcomes after non-cardiac surgery.^22–24^ Each study had multiple types of surgeries, most commonly describing abdominal/gastrointestinal, vascular, ophthalmologic, and orthopedic surgeries. Because studies did not all report similar outcomes, it was not possible to create graphs as was done for the CABG studies. We discuss each study narratively below.

Irie and colleagues identified 133 patients on DAPT post-cardiac stenting who underwent emergency non-cardiac surgery (majority abdominal, 57.9%, followed by vascular, 9%) and determined predictors of life-threatening and major bleeding within 180 days of surgery (N = 18) compared to those who did not (N = 115).^22^ There was no significant association between type of P2Y12 inhibitor and risk of bleeding (unadjusted). In addition, among the 18 patients who had major or life-threatening bleeding, 61% had restarted antiplatelet therapy less than 2 days after surgery compared to patients who did not develop these bleeding complications (61.1% vs 26.1%; unadjusted P = 0.005). After adjusting for potential confounders, overall survival did not significantly differ for patients with and without bleeding (180-day mortality: 4 [22.2%] in bleeding group vs 9 (7.8%) in no bleeding group; P = 0.06).

Cao and colleagues evaluated 747 patients who underwent non-cardiac surgery (mostly vascular, 33%, and gastrointestinal surgery, 23%) within 1 year of cardiac stenting and compared outcomes among those who interrupted antiplatelet therapy and those who did not.^23^ There was no association between antiplatelet therapy management and MACE after adjusting for patient factors and procedure urgency (adjusted odds ratio [aOR] = 1.23, 95% CI [0.55, 2.74], P = 0.62) or death within 30 days (aOR = 1.21, 95% CI [0.49, 2.98]). However, there was an 83% increased odds of bleeding (defined as >2 units transfused) among patients with no interruption of antiplatelet agent (aOR = 1.83, 95% CI [1.11, 3.01], P = 0.018), which the authors note tended to occur sooner after cardiac stenting.

The third study of antiplatelet management after cardiac stenting by Kim and colleagues compared discontinuing (N = 1750) versus continuing 1 or both antiplatelet agents (N = 1832) for at least 1 day prior to non-cardiac surgery across 9 institutions.^24^ Here, the most common types of surgeries that antiplatelet therapy was discontinued for included gynecologic, breast, head and neck, and intraabdominal surgeries, while other types such as vascular and ophthalmologic surgeries more often continued antiplatelet therapy. When comparing continuation versus discontinuation of antiplatelet therapy across all surgeries, the authors found no effect of antiplatelet discontinuation on MACE in a risk-adjusted Cox proportional hazards model (adjusted hazard ratio [HR] = 1.13, 95% CI [0.57, 2.24], P = 0.721) or in major bleeding when antiplatelet agents were discontinued (adjusted HR = 1.22, 95% CI [0.80, 1.87], P = 0.349). The authors also conclude that an optimal duration for discontinuing antiplatelet therapy is 4–8 days, as this was associated with the lowest risk of MACE (unadjusted HR = 0.12; 95% CI [0.03, 0.52], P = 0.019).

### Patients on Preoperative DAPT and Undergoing Surgery for Hip Fracture

We identified 1 retrospective study of 122 patients taking DAPT who sustained a hip fracture and require fixation or hip arthroplasty.^15^ Patients were taking DAPT for a variety of reasons, the majority (61%) for ischemic heart disease. The authors assessed whether the duration of DAPT discontinuation (which was the number of days until surgery) was associated with clinical outcomes. They found a small increased adjusted odds of 30-day mortality for each day of operative delay (OR = 1.32, 95% CI [1.03, 1.68], P = 0.030) but no association with total units transfused among 11 patients requiring transfusion (incidence rate ratio = 1.00, 95% CI [0.87, 1.15], P = 0.968). The odds of major complications also varied across time to surgery, ranging from a small increased odds at 3.5 days (OR = 0.20, 95% CI [0.08, 0.53]), reflecting a U-shaped relationship, to a substantial increased odds at 7 days (OR = 7.91, 95% CI [2.50, 25.0], P = 0.001). The authors concluded that there was no benefit to surgical delay after hip fracture for older adults on DAPT. This study design precluded separating out the effects of DAPT washout from the effects of other reasons for the medical delay.

### Patients on Preoperative DAPT and Undergoing Renal Transplant Surgery

Our search identified 1 study which compared antiplatelet interruption before renal transplantation in 106 patients with prior coronary stent placement.^25^ This study uniquely characterized medication strategy in relation to time since DAPT indication, namely placement of a coronary stent, as well as stent type. Patients were divided into an early interruption group, defined as having transplant surgery 3 months from placement of a second-generation drug eluting stent (DES); a late interruption group, defined as having surgery 3–12 months from DES placement; and a bare metal stent (BMS) group, defined as having surgery at least 1 month from BMS placement. As opposed to the other studies included in our review that varied perioperative DAPT management across comparison groups, in this study both ASA and clopidogrel were held 5–7 days prior to transplantation for all patients. The primary finding of this study was that there were no significant differences in cardiovascular clinical outcomes, including stent thrombosis (P = 0.465), myocardial infarction (P = 0.840), MACE (P = 0.840), and death (P = 0.411), for early versus late DAPT interruption after second generation DES or BMS placement. The authors conclude that early interruption of DAPT after stent placement in preparation for renal transplant surgery was a safe strategy and did not lead to increased ischemic complications.

### Major Adverse Limb Outcomes

We did not identify any studies reporting limb outcomes of any kind.

## KEY QUESTION 2 DOES OCCURRENCE OF MAJOR ADVERSE EVENTS VARY ACROSS DIFFERENT PATIENT SUBGROUPS (eg, INDICATION FOR DAPT [eg, CORONARY ARTERY DISEASE, STROKE, FOLLOWING STENT PLACEMENT], AGE, SEX, COMORBIDITY)?

Among the studies in this systematic review, all but one included patients whose indication for DAPT was coronary artery disease, acute coronary syndrome, or percutaneous coronary intervention with stent placement. Tarrant et al, which investigated the effect of DAPT management following hip surgery, was the only study to include and specify multiple different indications for DAPT (N = 122, ischemic heart disease 61%, cerebrovascular disease 31%, peripheral vascular disease 5%, and other 3%). In this study, outcomes were not reported according to the different indications.

However, 2 studies analyzed the impact of time between surgery and prior coronary stent placement. Specifically, these studies sought to examine the safety of performing surgery and briefly suspending DAPT within the period of so-called mandatory antiplatelet therapy after stent placement. In contemporary PCI, this is considered to be 3 months following new generation DES placement and 1 month following BMS placement. In an investigation of risk factors associated with bleeding in emergency non-cardiac surgery, bleeding occurred more frequently in patients who underwent surgery within 3 months after DES, though this difference was nonsignificant (4 patients in the bleeding group vs 11 in the non-bleeding group, P = 0.12).^22^ There was also no difference in bleeding for patients who underwent surgery within 30 days of BMS placement. The other article, by Dogan and colleagues, found that early interruption of DAPT 3 months from DES placement did not increase ischemic complications such as stent thrombosis, myocardial infarction, MACE, or death after renal transplantation. Outcomes were similar for patients treated with BMS. Notably, ST elevation myocardial infarction (STEMI) was excluded and the majority of these patients underwent PCI for stable angina, rather than acute coronary syndrome.

## CERTAINTY OF EVIDENCE

The certainty of evidence for each of the outcomes and DAPT management strategies is shown in Table 1 below. In general, all outcomes were judged to have serious limitations due to study design and execution issues and there were no RCTs available. All outcomes were judged to have no limitations due to directness, as the outcomes measured were judged to be both sufficiently accurately assessed and the outcomes that matter to patients. All outcomes were judged to have limitations due to imprecision, even if the directionality of results was consistent. Some outcomes were judged to have inconsistent results across studies (bleeding, transfusions, re-explorations, etc), while some other outcomes were judged to be consistent, in part because there were so few studies (re-explorations, MACE outcomes), these latter all being judged as very low certainty evidence. In sum, there were no outcomes/DAPT strategy choices that were judged to be high or even moderate certainty of evidence. A few bleeding outcomes were judged to be low certainty evidence, and all other outcomes, including other possible interventions (bridging, other potential antiplatelet therapy [APT] variations) and all other outcomes (including limb outcomes), were judged to be very low certainty evidence since there was either a single observational study or no studies informing the decision.

Table 1 GRADE for Certainty of Evidence

Outcome | Study Limitations | Consistency | Directness | Precision | Certainty of Evidence
Holding DAPT for More Than 2 Days vs Less Than ≤2 Days
CABG Surgery
Bleeding is less | Serious limitations | Inconsistent | Direct | Imprecise | Low
Transfusion is less | Serious limitations | Inconsistent | Direct | Imprecise | Low
Re-exploration is less | Serious limitations | Inconsistent | Direct | Imprecise | Low
Holding DAPT vs Continuing DAPT
CABG Surgery
No difference in bleeding | Serious limitations | Inconsistent | Direct | Imprecise | Very low
No difference in transfusions | Serious limitations | Inconsistent | Direct | Imprecise | Low
No difference in re-exploration | Serious limitations | Consistent | Direct | Imprecise | Very low
Non-cardiac Surgery
Bleeding is less | Serious limitations | Inconsistent | Direct | Imprecise | Very low
No difference in MACE/cardiac outcomes | Serious limitations | Consistent | Direct | Imprecise | Very low