# METHODS

## KEY QUESTIONS

The following key questions (KQs) were the focus of this review:

KQ1 Among adults on DAPT undergoing major elective, urgent, or emergent surgeries, what is the occurrence of major adverse events when DAPT is continued versus suspended or varied perioperatively?
KQ2 Does occurrence of major adverse events vary across different patient subgroups (eg, indication for DAPT [eg, coronary artery disease, stroke, following stent placement], age, sex, comorbidity)?

## PROTOCOL

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (http://www.crd.york.ac.uk/PROSPERO/; registration number: CRD42022371032).

## DATA SOURCES AND SEARCHES

We conducted broad searches using terms relating to dual anti-platelet therapy or double anti-platelet or DAPT and general surgery or surgical procedures, operative. To identify articles relevant to the key questions, a research librarian searched PubMed and Cochrane from 11/30/2015–5/16/2021 and Embase from 1/1/2016–5/17/22. We limited the search to published and indexed articles involving human subjects available in the English language. Study selection was based on the eligibility criteria described above. See Appendix A for complete search strategy.

## STUDY SELECTION

Four team members working independently screened the titles of retrieved citations. For titles deemed relevant by at least 1 person, abstracts were then screened independently by 2 team members. All disagreements were reconciled through group discussion. Full-text review was conducted in duplicate by independent team members with any disagreements resolved through discussion. Studies were included at the full-text level if they were original research studies of any design and had relevant outcome data presented for the patients that were on preoperative DAPT comparing at least 2 perioperative strategies.

The ESP included studies that met the following criteria:

Population: | Adults on DAPT for any reason undergoing major elective, urgent, or emergent surgeries
Intervention: | Continued DAPT in the perioperative period
Comparator: | Suspended or varied DAPT (ie, by drug or by timing) in the perioperative period
Outcomes: | Occurrence of major adverse cardiac events (MACE and myocardial infarction [MI], stroke, cardiovascular death), major adverse limb events (MALE), all-cause death and major bleeding (standardized bleeding according to Thrombolysis in Myocardial Infarction [TIMI] or Bleeding Academic Research Consortium [BARC] scores, or transfusions or blood loss) and reoperation
Timing: | 2015–present
Setting: | Any
Study Design: | Original research studies of any design

## DATA ABSTRACTION

Data extraction was completed in duplicate. All discrepancies were resolved with full-group discussion. At the abstract stage, information on the eligibility (whether patients were on preoperative DAPT, whether there was a comparison of patients on preoperative DAPT with at least 2 alterative preoperative or postoperative management groups, and whether there were postoperative outcomes included), sample size, and study design were collected. Articles meeting inclusion criteria underwent a second screening, and additional information was abstracted including categorization of comparison groups for each DAPT management strategy, patient characteristics, DAPT indication, and outcomes. Bleeding outcomes of interest were mean postoperative blood loss, reoperation for blood loss, red blood cell transfusions, platelet transfusions, and the occurrence of bleeding events classified by standardized criteria such as the TIMI and/or BARC systems. Cardiovascular outcomes of interest were myocardial infarction, stroke, revascularization, cardiovascular death, MACE (defined as the composite of total death, MI, stroke, hospitalization for heart failure, and revascularization), net adverse cardiovascular events (NACE, defined as MACE plus major bleeding), MALE (defined as severe limb ischemia leading to an intervention or major vascular amputation), and cardiovascular death. Data on all-cause mortality were also collected.

## RISK OF BIAS ASSESSMENT

To assess the risk of bias, we used the Risk of Bias in Non-randomized Studies – of Interventions (ROBINS-I).^13^ We used ROBINS-I for observational studies. This tool requires an assessment of whether a study is at critical, serious, moderate, or low risk of bias (or no information) in 7 domains: confounding, selection bias, bias in measurement classification of interventions, bias due to deviations from intended interventions, bias due to missing data, bias in measurement of outcomes, and bias in selection of the reported result (see Appendix C for tool and Appendix D for table).

## SYNTHESIS

Because studies differed significantly in DAPT strategies and outcomes measured, no meta-analytic analysis was judged clinically sensible. Therefore, the synthesis is narrative, looking at different DAPT strategies, the types of surgical procedures (predominantly coronary artery bypass graft surgery [CABG]), and outcomes. In this report, we consider withdrawal or discontinuation of DAPT as stopping either aspirin or a P2Y12 inhibitor or both agents; continuation of DAPT indicates that both drugs were given in the specified timeframe.

Continuous outcomes were analyzed by using the mean or median along with a measure of dispersion (standard deviation, interquartile range) to calculate the difference and 95% confidence intervals (CI) between arms. For binary outcomes, outcome counts were used to calculate risk differences and corresponding 95% CI. Risk differences were preferred because they allow for rare events and outcomes with zero events. When a study reported an eligible outcome only as an odds ratio, we converted outcome data from other studies to odds ratios. We created figures for outcomes with 3 or more studies and included all outcomes in Appendix E. Graphical representations of effect sizes (mean difference, risk difference, or odds ratio) and 95% CI were plotted when available or able to be estimated using counts and sample sizes using the metafor package in R version 4.0.2 (R Foundation for Statistical Computing, Vienna, Austria).

## CERTAINTY OF EVIDENCE

We used the criteria of the Grading of Recommendations Assessment, Development and Evaluation (GRADE) working group.^14^ GRADE assesses the certainty of the evidence based on the assessment of the following domains: risk of bias, imprecision, inconsistency, indirectness, and publication bias. This results in the following categories:

- High: We are very confident that the true effect lies close to that of the estimate of the effect.
- Moderate: We are moderately confident in the effect estimate. The true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.
- Low: Our confidence in the effect estimate is limited. The true effect may be substantially different from the estimate of the effect.
- Very Low/Insufficient: We have very little confidence in the effect estimate. The true effect is likely to be substantially different from the estimate of the effect.