# INTRODUCTION

## PURPOSE

The Evidence Synthesis Program (ESP) is responding to a request from Jason Johanning, Medical Director, Surgical Quality Improvement Program in National Surgery Office, to review the evidence on the occurrence of major adverse events associated with continuing, suspending, or varying dual antiplatelet therapy (DAPT) in the perioperative period. Findings from this review will be used to inform guidance on the management of DAPT in the perioperative period for patients undergoing major elective, urgent, or emergent surgeries.

## BACKGROUND

Antiplatelet agents are central in the management of cardiovascular and cerebrovascular disease. DAPT consisting of aspirin and a P2Y12 antagonist is protective against recurrent myocardial infarction, coronary stent thrombosis after percutaneous coronary intervention (PCI), and cerebrovascular ischemic events.^1–5^ The benefits of DAPT in terms of thromboembolic prevention must be weighed against bleeding risk. This balance is especially critical in patients undergoing both cardiac and non-cardiac surgery. An estimated 5% of patients with coronary stents may need non-cardiac surgery within 1 year and up to 25% undergo surgery within 5 years.^6,7^ A significant proportion of patients who are on DAPT may also require cardiac surgery.^8–10^

The optimal perioperative management of antiplatelet agents for patients on DAPT is not clear. Current international guidelines recommend delaying elective surgery for 1 to 6 months after stent placement and continuing aspirin through the perioperative period if the surgery cannot be delayed and when the procedure mandates discontinuation of a P2Y12 inhibitor.^9,10^ However, there is limited evidence to guide decision-making involving urgent surgical intervention or patients with significant ischemic or bleeding risks. These situations pose a particular challenge to clinicians who must consider the consequence of delaying surgery, the hazard of periprocedural bleeding, and the risk of thrombotic events in patients with known cardiovascular disease.

In 2016 and 2017, the ESP produced 2 reports on antiplatelet therapy management for patients with stents undergoing elective surgery: 1 report focused on patients with cardiac stents^11^ and the other on patients with peripheral vascular or cerebrovascular stents.^12^ Both reports concluded that insufficient evidence was available at that time to offer clear guidance for clinical practice. In the intervening years, the urgency of the need for evidence for this clinical decision has grown, and thus ESP was engaged to search for current evidence since 2015 regarding the occurrence of major adverse events associated with continuing, suspending, or varying DAPT in the perioperative period.