# APPENDIX F PEER REVIEW DISPOSITION

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 2 | Yes | Thank you.
2 | 3 | Yes | Thank you.
3 | 5 | Yes | Thank you.
4 | 6 | Yes | Thank you.
Is there any indication of bias in our synthesis of the evidence?
5 | 2 | No | Thank you.
6 | 3 | No | Thank you.
7 | 5 | No | Thank you.
8 | 6 | No | Thank you.
Are there any published or unpublished studies that we may have overlooked?
9 | 2 | Yes - Grzegorz L. Kaluza MD, PhD, Jane Joseph, Joseph R. Lee MD, Michael E. Raizner MD and Albert E. Raizner MD, Catastrophic outcomes of noncardiac surgery soon after coronary stenting Catastrophic outcomes of noncardiac surgery soon after coronary stenting FACC 2000 25:5 1288–1294 . | We reviewed this study and do not think it meets eligibility criteria, as it does not report the details on pre-op DAPT management or present different treatment strategies
10 | 3 | No | Thank you.
11 | 5 | No | Thank you.
12 | 6 | Yes - Douketis JD, Spyropoulos AC, Murad MH, . Perioperative Management of Antithrombotic Therapy: An American College of Chest Physicians Clinical Practice Guideline. Chest. 2022;162(5):e207–e243. doi:10.1016/j.chest.2022.07.025 35964704 | We reviewed this study. It is a practice guideline and thus not primary evidence. We do cite it in the discussion.
12 | 6 | Devereaux PJ, Mrkobrada M, Sessler DI, . Aspirin in patients undergoing noncardiac surgery. N Engl J Med. 2014;370(16):1494–1503 24679062 | We reviewed this study, it is about ASA therapy and not about DAPT
12 | 6 | Antolovic D, Reissfelder C, Rakow A, . A randomised controlled trial to evaluate and optimize the use of antiplatelet agents in the perioperative management in patients undergoing general and abdominal surgery--the APAP trial (ISRCTN45810007). BMC Surg. 2011;11:7. Published 2011 Mar 3.21371292 | We reviewed this study. This is the protocol for a study, and does not contain any study results
12 | 6 | Wang A, Wu A, Wojdyla D, . Dual antiplatelet therapy for perioperative myocardial infarction following CABG surgery. Am Heart J. 2018;199:150–155.29754654 | We reviewed this study. Not all of these patients are on pre-op DAPT and therefore it does not meet the inclusion criteria
12 | 6 | Burdess A, Nimmo AF, Garden OJ, . Randomized controlled trial of dual antiplatelet therapy in patients undergoing surgery for critical limb ischemia. Ann Surg. 2010;252(1):37–42.20562608 | We reviewed this study. Not all of these patients are on pre-op DAPT and therefore it does not meet the inclusion criteria.
Additional suggestions or comments can be provided below.
13 | 2 | Note: I used the page numbers for the PDF not the page numbers on the pages in the PDF. So when I say Page 11 (from the PDF) that is page 8 of the report.
13 | 2 | Comments:
13 | 2 | Page 4&5: No anesthesia authors on review panel. Heavy surgical presence. No input from highest risk for DAPT surgical field, neurosurgery. | Lacking an anesthesiologist among our technical experts is a limitation we acknowledge. The lack of a neurosurgeon we don’t consider a significant limitation since there were no eligible studies of neurosurgical procedures.
14 | 2 | Page 12: With only 19 studies (1 RCT and 18 Observational Studies) review of literature is unlikely to find a result. I know it is against your charge but epidemiologic analysis of data from the VA CDW is likely to provide superior information to your review of the literature. On the time of NPO to scope ESP, there were no conclusions possible from the literature. Epidemiologic analysis of CDW data provided meaningful results that were vastly more informative than the no conclusion possible from literature review. | Thank you. In our Future Research section, we suggest the VA QUIP database as a potential data source that could provide answers to our clinical questions. If the database has preoperative data on DAPT use and indication in addition to perioperative DAPT management, then analyzing this would benefit from the considerable existing work done to develop risk adjusting models.; We included your suggestion to also consider patient data from the CDW as another potential data source for analysis.
15 | 2 | Page 12: CABG and cases that utilize cardiopulmonary bypass are fundamentally different from all non-cardiac surgery and should not be included with analysis from non-cardiac surgery. | In our draft report we did not lump together CABG and non-CABG cases, except for the one publication which did so. To make it more clear that we kept these separate we revised the wording in the Executive Summary to discuss CABG surgery and noncardiac surgery separately. We also present our findings for cardiac surgery separately from noncardiac surgery in the Results section of the Evidence Report.
16 | 2 | Page 13 Line 3 “less blood less” I think you mean “loss”. This paragraph is not interpretable for a very simple reason. If you lump cardiac surgery with non-cardiac surgery with neurosurgery, you will get meaningless results. All cardiac surgical cases, that use extracorporeal circulatory support, damage the coagulation system. They must be analyzed separately from surgical cases that do not use bypass. Vascular surgery cases have a lower risk of hemorrhage and a greater benefit from DAPT. They must be analyzed separately. Cases where hemorrhage will be lethal or cause profound neurologic injury such as neurosurgery, must be analyzed separately. You can’t lump all these things together and then talk about blood loss, it is non-sensical. Blood loss of 1-2 liters is standard in CABG, a problem in vascular cases but not unexpected, and lethal in intracranial surgery. They must be analyzed separately to have any meaning. | Thank you. Please see the above comment. This paragraph is now referring only to studies involving CABG. The following paragraph discusses results from the single combined cardiac and noncardiac surgery and the remaining studies involving only noncardiac surgery.
17 | 2 | Page 13 Line 22. When we did the ESP for GI NPO, I said and I quote “There is nothing in the literature that will indicate the risk from aspiration pneumonia and the risk of misdiagnosis because the sample sizes are too small, you must do epidemiologic analysis of data from the CDW.” The published literature can’t answer these questions. You must recognize this fault prior to doing an ESP, and do epidemiologic analysis of CDW data which will likely give you insight. This is the third ESP I have seen (two for DAPT and one for GI NPO) with no result that likely would have a result if you changed your mission statement to do epidemiologic analysis of VA CDW data when the literature has no chance to answering the question. | We appreciate your insight. Please see Comment #14 above. We included your suggestion to perform an epidemiologic analysis using CDW data in the Future Research section, although if VA-QUIP has the data it would be far easier to do so with its standardized data collection and risk-adjusting models already created.
18 | 2 | Page 13 Line 40 Future Research: Absolutely, this can and should be done. ESP with no chance of success are a waste of time. | Thank you. Please see above.
19 | 2 | Page 20 Line 21. The Turkish study is a comparison of four approaches to managing emergency patients all of whom are on DAPT (TXA, TXA+Desmopressin, Desmopressin, Nothing). This will only tell you if TXA or Desmopressin reduce risk of bleeding in patients on DAPT. It won’t tell you what the effect of taking DAPT is versus not. What does this RCT, the only RCT in your ESP have to do with the risk of DAPT? There is no control group off DAPT. | Thank you; while we initially included this study because it tested a perioperative management strategy to mitigate the effect of DAPT, upon further review, we agree that it is outside the scope of our key questions since it did not vary or alter the DAPT itself. Thus, we excluded the article with subsequent alterations made in the report text.
20 | 2 | Page 22 Line 43. How much less blood loss. 250 ml less blood loss, in the face of an average of 1-2 liters, is interesting but not clinically significant. A liter difference would be clinically significant difference. You need to know the difference that was detected to make this paragraph contributory. My guess from the graph is the average of all the studies is 125 ml, which is something you can write a paper about but is clinically not significant in CABG surgery. | We added information about the quantity of blood loss from the relevant studies. The question of whether or not this is clinically significant is raised in the Discussion section.
21 | 2 | Page 23 Line 38 Transfusion differences are clinically significant results. 4 of 9 fewer patients needing transfusion is interesting but 5 of 9 with no difference is consistent with the guess of 125 ml average additional blood loss. | Agreed. Thank you.
22 | 2 | Page 24 Line 37 The requirement for surgical re-exploration after CABG for bleeding increases perioperative risk. Avoiding re-exploration requirements is important. Can you conclude there is less need for re-exploration if DAPT is discontinued more than 2 days before surgery? That would be an important conclusion. Figure 3 shows one study concluded a 20% reduction in the need for re-exploration,1 out of 5 at 20% reduction, likely isn’t meaningful. | The data are not conclusive as 2 of the 5 studies comparing DAP withdrawal strategies prior to surgery were not significant. However, 3 of the studies do show statistically significant differences in reoperation risk and there is an overall trend in all these studies favoring withdrawal >2 days. We believe that this is clinically meaningful but acknowledge the limitations of the data in future sections of the report.
23 | 2 | Page 26 Figure 4. My guess is a large epidemiologic analysis of CDW data would show an increase in mortality from DAPT. In the McSPI dataset, there was a 10 fold increased risk in patients who were on coumadin within 7 days of CABG. There is likely some additional risk from DAPT but you need to do a large epidemiologic analysis of CDW data to show it. | Thank you. We included your suggestion to perform an epidemiologic analysis using CDW data in the Future Research section.
24 | 2 | Page 27 Line 30 Some discussion of how long the DAPT was discontinued would help make this section more interpretable. I would exclude all ophthalmic cases. Most of these are intraocular lens which doesn’t cut through any blood vessels. The chance of bleeding is zero. Adding IOL cases into general surgery just confuses the results. Is this a week of discontinuation or 2 days? When did they restart the DAPT? | This study reports the ophthalmic cases grouped with all the other surgeries, so it cannot be excluded from analysis. However, we adjusted the paragraph to more clearly explain the study’s findings. Information was added about how long DAPT was held preop, surgery types in which antiplatelet therapy was continued vs held, and DAPT duration.
25 | 2 | Page 27 Line 35 This may be the most important study so far. There are two effects here. The first is the mortality effect of delaying ORIF in hip fractures. Each day of delay has an effect on mortality. The second effect is the increased risk from holding DAPT. These two risks are combined to get the OR 7.91 at one week. There are two risks here that are hard to separate. | Thank you for the comment. We agree that they may be measuring increased risk from two phenomenon: the surgical delay after hip fracture and the impact of holding DAPT. Since these factors were dependent on one another, we agree that they are hard to separate and added text to acknowledge this limitation.
26 | 2 | Page 27 Line 51 This is an important study as it contradicts Grzegorz L. Kaluza MD, PhD, Jane Joseph, Joseph R. Lee MD, Michael E. Raizner MD and Albert E. Raizner MD, Catastrophic outcomes of noncardiac surgery soon after coronary stenting Catastrophic outcomes of noncardiac surgery soon after coronary stenting FACC 2000 25:5 1288–1294 . I am surprised that they were really able to discontinue clopidogrel for 5-7 days. These must not be cadaveric transplants because there is rarely a 5-7 preoperative warning on a cadaveric transplant. Were these donor related transplants? If not, the results should be looked at carefully to see how they got a 5-7 preoperative time to hold DAPT for a cadaveric transplant. | Thank you for this interesting observation. We think there are several potential explanations as to why the Dogan study included in our analysis seems to contradict the article by Grzegorz et al. All patients in this study underwent renal transplant from living donors. Importantly, the Grzegorz study was published in the early PCI era, when only BMS or first-generation DES were available. The Dogan study is a more contemporary analysis that includes only second-generation DES and newer BMS, which have shown to be protective of cardiac ischemic complications. Finally, the average time from stent placement to surgery in the Gzregorz study was 13 days compared to 3 months in the early DES discontinuation group and 1 month in the BMS group in the Dogan study.
27 | 2 | Page 31 Line 6 We need a large epidemiologic study of the VA CDW data to answer this question. I said this after the 2016 ESP concluded with a similar limitation. | Thank you. We have added this suggestion to the Future Research section.
28 | 2 | Page 31 Line 32 You have an extra period. “Bias. .Further” | This has been corrected, thank you.
29 | 2 | Page 31 Line 55 There are a number of clinical questions we face every day. 1. Patient for CABG, with prior PCI, on DAPT, how long do you discontinue the DAPT? 2. Patient for vascular surgery, like a AAA, with prior PCI, on DAPT, how long do you discontinue DAPT? 3. Same vascular surgery patient for Fem Distal. 4. Patient for general surgery, prior PCI, on DAPT, for exploratory laparotomy. Can we give ASA? Do we continue the clopidogrel? What is risk of MACE? We need an analysis of the CDW data to see the answers to these questions, ESP won’t give us the answer. | Please see additional comments which include your suggestion to consider the CDW as a potential source for an epidemiologic analysis.
30 | 2 | Page 32 Line 20. I guarantee the data is in the VA CDW to answer this question. | Thank you for this suggestion. We include this as a possible avenue for future research.
31 | 3 | Balanced, thoughtful, and clear evaluation of available literature and clearly stated limitations. Did any studies look at continuing one agent rather than holding both agents? There is increasing interest/use of P2Y12i monotherapy in practice. Understand using >/< 2 days timeframe for DAPT DC, but noted some studies looked at significantly longer DC periods (e.g., 7 days) which could be expected to have different outcomes than shorter timeframes. Should this be evalauted or mentioned as a limitation? Suggest recognizing/addressing the 2021 ACC/AHA/SCAI revasc guideline recs for holding APT around CABG surgery (the most common setting studied) and how those fit with your findings. Suggest recognizing potential for differences in the PK/PD profiles of individual P2Y12i and possible need for different hold guidance rather than generic “class” guidance - e.g., how was this issue evaluated in the literature and what are future research needs. Last, the renal transplant study would not be generalizable or extrapolated to other settings - should this be stated? | Thank you. The majority of the studies compared dual antiplatelet therapy with single antiplatelet therapy given that current guidelines recommend continuing aspirin through the perioperative period when possible. In our analysis we considered holding either or both ASA or a P2Y12 inhibitor as discontinuing or withholding DAPT. This was clarified in our Methods section.; We appreciate your point about prolonged DAPT withholding duration influencing the aggregate results. We added this as a limitation of our analysis.; We added a reference to the 2021 ACC/AHA/SCAI revascularization guidelines and compare these to our results in the Discussion section.; We also included the limitation you mention in grouping P2Y12 inhibitors together despite differences in PK/PD profiles.; The generalizability of all studies is open to question, as surgical protocols and post-operative care may differ among hospitals, even for procedures given the same name, like “cholecystectomy”. We don’t think we need to call out this one study in specific for generalizability.
32 | 3 | p19-l42 - typo and suggested reword - “point estimate favored less blood loss” | Thank you; this has been reworded.
33 | 3 | p55-L19 - 2019 Irie study - is ticlopidine correct or is it ticagrelor? | Yes, Ticlopidine is correct.
34 | 5 | page iii - line 27, add ‘the’ before Surgical Quality Improvement Program | This has been corrected, thank you.
35 | 5 | page 10, line 43 and page 29 line 9 - unclear wording of #1 - perhaps change to “to have a very large sample” or change first part of sentence to “The attributes of such an observational study would include:” | Thank you. We changed the wording here.
36 | 5 | Figure 1 - please explain “Exclude:all else” or just label as “other reasons’ | Thank you, this has been changed to “other reasons”.
37 | 5 | page 48, citation of Nardi is cut off, so unable to see what Group C was. Consider reformatting table. | This appears to be fixed in our current version.
38 | 6 | The manuscript sets out to discuss Dual Antiplatelet Management in the Perioperative Period but does not mention relevant clinical trials (presented in the comment box above), contemporary recommendations made by professional guidelines, or manufacturers. Please consider adding the following pertinent information: | We have added where relevant any published studies meeting the inclusion criteria, and in the Discussion have now mentioned the various guidelines and manufacturers information.
39 | 6 | When possible, interrupt therapy with ticagrelor for five days prior to surgery that has a major risk of bleeding. Brilinta. Prescribing information. AstraZeneca; 2022. | Thank you. This has been added to the Discussion section.
40 | 6 | When possible, discontinue prasugrel at least 7 days prior to any surgery. Effient. Prescribing information. Eli Lilly and Company; 2020.; Discontinue [clopidogrel] 5 days prior to elective surgery that has a major risk of bleeding. Plavix. Prescribing information. Sanofi-Aventis; 2022.; Stopping aspirin 3 or more days prior to surgery has been investigated in the POISE-2 trial < Devereaux PJ, Mrkobrada M, Sessler DI, . Aspirin in patients undergoing noncardiac surgery. N Engl J Med. 2014;370(16):1494–1503.24679062 > | Thank you. This has been added to the Discussion section.
41 | 6 | CHEST guideline recommendations for P2y12 antagonists:; Stop ticagrelor 3 to 5 days instead of 7 to 10 days before the surgery.; Stop prasugrel 7 days instead of 7 to 10 days before the surgery.; Stop clopidogrel 5 days instead of 7 to10 days before the surgery.; < Douketis JD, Spyropoulos AC, Murad MH, . Perioperative Management of Antithrombotic Therapy: An American College of Chest Physicians Clinical Practice Guideline. Chest. 2022;162(5):e207–e243. doi:10.1016/j.chest.2022.07.025 35964704 > | Thank you. This has been added to the Discussion section.
42 | 6 | In patients receiving aspirin who are undergoing elective non-cardiac surgery, CHEST guidelines suggest aspirin continuation over aspirin interruption. In those who require aspirin interruption, CHEST guidelines suggest stopping ASA 7 or less days instead of 7 to 10 days before the surgery. < Douketis JD, Spyropoulos AC, Murad MH, . Perioperative Management of Antithrombotic Therapy: An American College of Chest Physicians Clinical Practice Guideline. Chest. 2022;162(5):e207–e243. doi:10.1016/j.chest.2022.07.025 35964704 > | This is now cited in the Discussion.
43 | 6 | DATA Sources page 13 lines 27-35:; Other search term should include “Perioperative”; Furthermore, search term should be Dual “antiplatelet” instead of “anti-platelet” as the former is widely recognized as the preferred spelling. For example, a PUBMED search using ((antiplatelet) AND (dual)) AND (perioperative) will yield significantly more results than if “antiplatelet” is replaced with “anti-platelet” | The spelling of “antiplatelet” is not an issue since in the search strategy both spellings are used, linked with an “OR”, meaning the search will identify either spelling.; We added “peri-operative” and “perioperative” to our search and it only found 16 additional titles, none of which met eligibility criteria, and thus it is not a limitation of the original search to have not included these terms.
44 | 6 | Page 10; Lines 3-4 - please clarify sentence “The preponderance of point estimated favor less blood less with longer duration of suspension of DAPT therapy for at least 2 days.” Did the authors intend to state “point estimates favor less blood loss”? | Yes, we meant to state “less blood loss.” This has been corrected.