# APPENDIX D QUALITY ASSESSMENT FOR INCLUDED OBSERVATIONAL STUDIES

Author, Year | Bias Due to Confounding | Bias in Selection of Participants | Bias in Classification of Interventions | Bias Due to Deviations from Intended Interventions | Bias Due to Missing Data | Bias in Measurement of Outcomes | Bias in Selection of Reported Results
Cao, 2022^23^ | Moderate | Low | Low | Low | Low | Low | Low
Cheng, 2020^27^ | Moderate | Low | Low | Low | Moderate | Low | Moderate
De Servi, 2016^28^ | High | Low | Moderate | Low | Low | Low | Low
Della Corte, 2017^18^ | Moderate | Low | Low | Moderate | Low | Low | Moderate
Doğan, 2017^25^ | Moderate | Moderate | Low | Low | Low | Low | Low
Gielen, 2015^29^ | Moderate | Moderate | Low | Low | Low | Moderate | Low
Hansson, 2016^30^ | Moderate | Low | Low | Low | Low | Low | Low
Heidari, 2016^21^ | High | High | Low | Low | Low | Moderate | Moderate
Irie, 2019^22^ | Moderate | Moderate | Low | Low | Low | Low | Low
Kacar, 2018^19^ | Moderate | Low | Low | Low | Moderate | High | High
Kapoor, 2022^31^ | High | Moderate | Low | Low | Low | Moderate | Low
Kim, 2020^24^ | Moderate | Moderate | Low | Low | Low | Low | Low
Kremke, 2019^16^ | Low | Moderate | Low | Low | Low | Low | Moderate
Nardi, 2021^17^ | Moderate | Moderate | Low | Low | Low | Moderate | Low
Shahid, 2021^20^ | High | Moderate | Low | Low | Low | High | Moderate
Tarrant, 2020^15^ | Moderate | Moderate | Low | Low | Low | Moderate | Low
Vuilliomenet, 2019^32^ | Moderate | Low | Low | Low | Low | Moderate | Moderate
Zhu, 2018^33^ | High | Moderate | Low | Low | Low | Moderate | Moderate