# APPENDIX B EXCLUDED STUDIES

## No Relevant Outcome Data Presented for the Patients that were on Preoperative DAPT Comparing at Least 2 Perioperative Strategies, N = 38

1 Altun, G., ., Emergency coronary bypass surgery in patients under the influence of dualantiplatelet therapy: effects of tranexamic acid and desmopressin acetate. Turk J Med Sci, 2017. 47(6).
2 Amour, J., ., Prospective observational study of the effect of dual antiplatelet therapy with tranexamic acid treatment on platelet function and bleeding after cardiac surgery. Br J Anaesth, 2016. 117(6): p. 749–757.27956673
3 Awada, H., ., Pocket related complications following cardiac electronic device implantation in patients receiving anticoagulation and/or dual antiplatelet therapy: prospective evaluation of different preventive strategies. J Interv Card Electrophysiol, 2019. 54(3): p. 247–255.30460588
4 Benkö, T., ., One-year Allograft and Patient Survival in Renal Transplant Recipients Receiving Antiplatelet Therapy at the Time of Transplantation. Int J Organ Transplant Med, 2018. 9(1): p. 10–19.29531642
5 Charif, F., ., Dual antiplatelet therapy up to the time of non-elective coronary artery bypass grafting with prophylactic platelet transfusion: is it safe? J Cardiothorac Surg, 2019. 14(1): p. 202.31775803
6 Chemtob, R.A., ., Outcome After Surgery for Acute Aortic Dissection: Influence of Preoperative Antiplatelet Therapy on Prognosis. J Cardiothorac Vasc Anesth, 2017. 31(2): p. 569–574.28017673
7 Christersson, C., ., Comparison of warfarin versus antiplatelet therapy after surgical bioprosthetic aortic valve replacement. Heart, 2020. 106(11): p. 838–844.31757813
8 Cui, R.B.J., K.S. Ng, and C.J. Young, Complications Arising From Perioperative Anticoagulant/Antiplatelet Therapy in Major Colorectal and Abdominal Wall Surgery. Dis Colon Rectum, 2018. 61(11): p. 1306–1315.30239396
9 Dai, Y., ., Dual antiplatelet therapy increases pocket hematoma complications in Chinese patients with pacemaker implantation. Journal of geriatric cardiology, 2015. 12(4): p. 383–387.26347068
10 Deharo, J.C., ., Perioperative management of antithrombotic treatment during implantation or revision of cardiac implantable electronic devices: the European Snapshot Survey on Procedural Routines for Electronic Device Implantation (ESS-PREDI). Europace, 2016. 18(5): p. 778–84.27226497
11 Egholm, G., ., Dual anti-platelet therapy after coronary drug-eluting stent implantation and surgery-associated major adverse events. Thromb Haemost, 2016. 116(1): p. 172–80.27098806
12 Guo, J., ., Effects of Sarpogrelate Combined with Aspirin in Patients Undergoing Carotid Endarterectomy in China: A Single-Center Retrospective Study. Ann Vasc Surg, 2016. 35: p. 183–8.27238992
13 Hansson, E.C., ., Preoperative dual antiplatelet therapy increases bleeding and transfusions but not mortality in acute aortic dissection type A repair. Eur J Cardiothorac Surg, 2019. 56(1): p. 182–188.30657880
14 Howell, S.J., ., Prospective observational cohort study of the association between antiplatelet therapy, bleeding and thrombosis in patients with coronary stents undergoing noncardiac surgery. Br J Anaesth, 2019. 122(2): p. 170–179.30686302
15 Hudson, J.S., ., Hemorrhage associated with ventriculoperitoneal shunt placement in aneurysmal subarachnoid hemorrhage patients on a regimen of dual antiplatelet therapy: a retrospective analysis. J Neurosurg, 2018. 129(4): p. 916–921.29125410
16 Hussain, A., ., Is the use of dual antiplatelet therapy following urgent and emergency coronary artery bypass surgery associated with increased risk of cardiac tamponade? J Clin Transl Res, 2021. 7(2): p. 229–233.34104825
17 Jones, D.W., ., Dual antiplatelet therapy reduces stroke but increases bleeding at the time of carotid endarterectomy. J Vasc Surg, 2016. 63(5): p. 1262–1270.e3.26947237
18 Kawamoto, Y., ., Effect of antithrombic therapy on bleeding complications in patients receiving emergency cholecystectomy for acute cholecystitis. Journal of Hepato-Biliary-Pancreatic Sciences, 2018. 25(11): p. 518–526.30312537
19 Kyuchukov, D., I. Zheleva-Kyuchukova, and G. Nachev, Antithrombotic regimens in patients after coronary artery bypass grafting and coronary endarterectomy. Pharmacia, 2020. 67(3): p. 115–120.
20 Lin, S.Y., ., The Safety of Continuing Antiplatelet Medication Among Elderly Patients Undergoing Urgent Hip Fracture Surgery. Orthopedics, 2019. 42(5): p. 268–274.31355906
21 Mishu, M.D., ., Should Antiplatelet Therapy Be Withheld Perioperatively? The First Study Examining Outcomes in Patients Receiving Dual Antiplatelet Therapy in the Lower Extremity Free Flap Population. Plast Reconstr Surg, 2022. 149(1): p. 95e–103e.
22 Nagashima, Z., ., Impact of preoperative dual antiplatelet therapy on bleeding complications in patients with acute coronary syndromes who undergo urgent coronary artery bypass grafting. J Cardiol, 2017. 69(1): p. 156–161.26987791
23 Oh, T.K., C. Im, and I.A. Song, Antiplatelet Therapy in Patients Without a Coronary Stent and Mortality After Noncardiac Surgery. Journal of Surgical Research, 2020. 256: p. 61–69.32683058
24 Ohya, H., ., Comparison of the continuation and discontinuation of perioperative antiplatelet therapy in laparoscopic surgery for colorectal cancer: A retrospective, multicenter, observational study (YCOG 1603). Annals of Gastroenterological Surgery, 2021. 5(1): p. 67–74.33532682
25 Park, S.K., ., Risk of non-cardiac surgery after percutaneous coronary intervention with drug-eluting stents. Sci Rep, 2017. 7(1): p. 16393.29180679
26 Plicner, D., ., Preoperative platelet aggregation predicts perioperative blood loss and rethoracotomy for bleeding in patients receiving dual antiplatelet treatment prior to coronary surgery. Thrombosis research, 2015. 136(3): p. 519–525.26003782
27 Rossini, R., ., Antiplatelet therapy and outcome in patients undergoing surgery following coronary stenting: Results of the surgery after stenting registry. Catheter Cardiovasc Interv, 2017. 89(1): p. E13–e25.27404797
28 Sadeghi, R., ., Dual antiplatelet therapy before coronary artery bypass grafting in patients with myocardial infarction: a prospective cohort study. BMC Surg, 2021. 21(1): p. 449.34972501
29 Schaefer, A., ., Preoperative Ticagrelor administration leads to a higher risk of bleeding during and after coronary bypass surgery in a case-matched analysis. Interact Cardiovasc Thorac Surg, 2016. 22(2): p. 136–40.26519259
30 Schlachtenberger, G., ., Major Bleeding after Surgical Revascularization with Dual Antiplatelet Therapy. Thorac Cardiovasc Surg, 2020. 68(8): p. 714–722.32593177
31 Smith, B.B., ., Cardiac Risk of Noncardiac Surgery After Percutaneous Coronary Intervention With Second-Generation Drug-Eluting Stents. Anesth Analg, 2019. 128(4): p. 621–628.30169404
32 Straus, S., ., A Difference in Bleeding and Use of Blood and Blood Products in Patients who Were Preoperatively on Aspirin or Dual Antiplatelet Therapy Before Coronary Artery Bypass Grafting. Med Arch, 2018. 72(1): p. 31–35.29416215
33 Sun, J., ., Safety and feasibility study of holmium laser enucleation of the prostate (HOLEP) on patients receiving dual antiplatelet therapy (DAPT). World J Urol, 2018. 36(2): p. 271–276.29138929
34 Tianchetsada, N. and A. Suwanagool, Antithrombotic management and device-related bleeding complications in patients undergoing cardiac implantable electronic device implantations: A single-center study. Journal of the Medical Association of Thailand, 2018. 101(1): p. 33–39.
35 Ueoka, K., ., The influence of pre-operative antiplatelet and anticoagulant agents on the outcomes in elderly patients undergoing early surgery for hip fracture. J Orthop Sci, 2019. 24(5): p. 830–835.30709788
36 Xiao, F.C., ., Does preoperative dual antiplatelet therapy affect bleeding and mortality after total arch repair for acute type A dissection? Interact Cardiovasc Thorac Surg, 2022. 34(1): p. 120–127.34999809
37 Yoshimoto, M., ., Emergent cholecystectomy in patients on antithrombotic therapy. Sci Rep, 2020. 10(1): p. 10122.32572122
38 Yoshimoto, Y., ., Optimal use of antiplatelet agents, especially aspirin, in the perioperative management of colorectal cancer patients undergoing laparoscopic colorectal resection. World Journal of Surgical Oncology, 2019. 17(1).

## Endovascular, N = 3

1 Chinai, N., ., Single versus dual antiplatelet therapy following peripheral arterial endovascular intervention for chronic limb threatening ischaemia: Retrospective cohort study. PLoS One, 2020. 15(6): p. e0234271.32525925
2 Ghamraoui, A.K., ., Clopidogrel versus ticagrelor for antiplatelet therapy in transcarotid artery revascularization (TCAR) in the Society for Vascular Surgery Vascular Quality Initiative. J Vasc Surg, 2021.
3 Kronlage, M., ., Anticoagulation in addition to dual antiplatelet therapy has no impact on long-term follow-up after endovascular treatment of (sub)acute lower limb ischemia. Vasa, 2019. 48(4): p. 321–329.30958111

## DAPT Interruption Not Specified, N = 1

1 Humenberger, M., M. Stockinger, S. Kettner, J. Siller-Matula and S. Hajdu (2019). “Impact of Antiplatelet Therapies on Patients Outcome in Osteosynthetic Surgery of Proximal Femoral Fractures.” J Clin Med 8(12).

## Does Not Specify Dual Antiplatelet, N = 1

1 Hong, S. J., M. J. Kim, J. S. Kim, E. H. Kim, J. Lee, C. M. Ahn, B. K. Kim, Y. G. Ko, D. Choi, M. K. Hong and Y. Jang (2019). “Effect of Perioperative Antiplatelet Therapy on Outcomes in Patients With Drug-Eluting Stents Undergoing Elective Noncardiac Surgery.” [underlined: American Journal of Cardiology] 123(9): 1414–1421.30770090

## No Outcome of Interest, N =1

1 Kim, C., J. S. Kim, H. Kim, S. G. Ahn, S. Cho, O. H. Lee, J. K. Park, S. Shin, J. Y. Moon, H. Won, Y. Suh, J. R. Cho, Y. H. Cho, S. J. Oh, B. K. Lee, S. J. Hong, D. H. Shin, C. M. Ahn, B. K. Kim, Y. G. Ko, D. Choi, M. K. Hong and Y. Jang (2021). “Consensus decision-making for the management of antiplatelet therapy before non-cardiac surgery in patients who underwent percutaneous coronary intervention with second-generation drug-eluting stents: A cohort study.” [underlined: Journal of the American Heart Association] 10(8).

## Not at Least 2 Comparison Groups of Patients on DAPT, N = 1

1 Hu, S. B., Y. Hai, J. F. Tang, T. Liu, B. X. Liang and B. Q. Xue (2019). “Risk of bleeding in patients with continued dual antiplatelet therapy during orthopedic surgery.” [underlined: Chin Med J (Engl)] 132(8): 943–947.30958436

## Single Arm with Bridging, N = 1

1 Dargham, B. B., A. Baskar, I. Tejani, Z. Cui, S. Chauhan, J. Sum-Ping, R. A. Weideman and S. Banerjee (2019). “Intravenous Antiplatelet Therapy Bridging in Patients Undergoing Cardiac or Non-Cardiac Surgery Following Percutaneous Coronary Intervention.” Cardiovasc Revasc Med 20(9): 805–811.30579773

## TAVR, N =1

1 Hioki, H., Y. Watanabe, K. Kozuma, Y. Nara, H. Kawashima, A. Kataoka, M. Yamamoto, K. Takagi, M. Araki, N. Tada, S. Shirai, F. Yamanaka and K. Hayashida (2017). “Pre-procedural dual antiplatelet therapy in patients undergoing transcatheter aortic valve implantation increases risk of bleeding.” Heart 103(5): 361–367.27540180

## Unavailable, N = 1

1 Zhang, J., F. Huang, J. Yang, Q. Wu, Y. Liu, Y. Zhou, Y. Zou and E. Zhu (2015). “Impact of preoperative dual antiplatelet therapy on perioperative bleeding in patients undergoing off-pump coronary artery bypass grafting.” [underlined: National medical journal of china] 95(24): 1934–1937.26710697