# APPENDIX A SEARCH STRATEGIES

## PubMed

11/30/2015-5/16/22; English Language

“Dual Anti-Platelet Therapy”[Mesh] OR “dual antiplatelet*”[tiab] OR “dual anti-platelet*”[tiab] OR DAPT[tiab] OR “double antiplatelet*”[tiab] OR “double anti-platelet*”[tiab] OR ((“Platelet Aggregation Inhibitors”[Mesh] OR “Factor Xa Inhibitors”[Mesh]) AND “Drug Therapy, Combination”[Mesh:NoExp])

AND

“General Surgery”[Mesh:NoExp] OR “Surgical procedures, operative”[mh] OR surgery[tiab] OR surgeries[tiab] OR surgical[tiab] OR operation[tiab] OR operations[tiab] OR amputat*[tiab] OR amputation[Mesh]

Results: 2597

## Cochrane

11/30/2015-5/16/22; English Language

[mh “Dual Anti-Platelet Therapy”] OR (([mh “Platelet Aggregation Inhibitors”] OR [mh “Factor Xa Inhibitors”]) AND [mh ^“Drug Therapy, Combination”]) OR (“dual antiplatelet*” OR “dual anti-platelet*” OR DAPT OR “double antiplatelet*” OR “double anti-platelet*”):ti,ab

AND

[mh ^“General Surgery”] OR [mh “operative surgical procedures”] OR [mh amputation] OR (surgery OR surgeries OR surgical OR operation OR operations OR amputation*):ti,ab

Results: 278

## Embase

1/1/2016-5/17/22; English

‘dual antiplatelet therapy’/exp OR (“dual antiplatelet*” OR “dual anti-platelet*” OR DAPT OR “double antiplatelet*” OR “double anti-platelet*”):ti,ab OR ((‘antithrombocytic agent’/exp OR ‘blood clotting factor 10a inhibitor’/exp) AND ‘combination drug therapy’/de)

AND

“General Surgery”/de OR ‘amputation’/exp OR “operative surgical procedures”/de OR (surgery OR surgeries OR surgical OR operation OR operations OR amputat*):ti,ab

Results: 2215