# ABBREVIATIONS TABLE

APT: Antiplatelet therapy
ASA: Acetylsalicylic acid
BARC: Bleeding Academic Research Consortium
BMS: Bare metal stent
CABG: Coronary artery bypass graft surgery
CDW: VA Corporate Data Warehouse
DAPT: Dual antiplatelet therapy
DES: Drug eluting stent
GRADE: Grading of Recommendations Assessment, Development and Evaluation
MACE: Major adverse cardiac events
MALE: Major adverse limb events
MI: Myocardial infarction
NACE: Net adverse cardiovascular events
PCI: Percutaneous coronary intervention
ROBINS-I: Risk of Bias in Non-randomized Studies – of Interventions
STEMI: ST elevation myocardial infarction
TAVR: Transcatheter aortic valve replacement
TIMI: Thrombolysis in myocardial infarction
QUIP: VA Surgical Quality Improvement Program