# REFERENCES

1 Murray CJL, Ikuta KS, Sharara F, . Global burden of bacterial antimicrobial resistance in 2019: a systematic analysis. The Lancet. 2022/02/12/ 2022;399(10325):629–655. doi:10.1016/S0140-6736(21)02724-0
2 Prevention USCfDCa. Outpatient Antibiotic Prescriptions — United States, 20221. https://archive.cdc.gov/#/details?url=https://www.cdc.gov/antibiotic-use/data/report-2022.html
3 Prevention USCfDCa. Outpatient Antibiotic Prescribing in the United States. https://www.cdc.gov/antibiotic-use/hcp/data-research/antibiotic-prescribing.html
4 Prevention USCfDCa. Core Elements of Outpatient Antibiotic Stewardship. https://www.cdc.gov/antibiotic-use/hcp/core-elements/outpatient-antibiotic-stewardship.html
5 Drekonja DM, Filice GA, Greer N, . Antimicrobial Stewardship in Outpatient Settings: A Systematic Review. Infection Control & Hospital Epidemiology. 2015;36(2):142–152. doi:10.1017/ice.2014.41 25632996
6 Development OfEC-oa. OECD. https://www.oecd.org/
7 RE-AIM. RE-AIM. https://re-aim.org/
8 Sterne J, Savovic J, Page M, . RoB 2: A revised tool for assessing risk of bias in randomised trials. BMJ. 2019;366
9 Peterson J, Welch V, Losos M, Tugwell P. The Newcastle-Ottawa scale (NOS) for assessing the quality of nonrandomised studies in meta-analyses. Ottawa: Ottawa Hospital Research Institute. 2011;2(1):1–12.
10 Viechtbauer W. metafor: Meta-Analysis Package for R. https://cran.r-project.org/web/packages/metafor/index.html
11 van Staa TP, Palin V, Brown B, Welfare W, Li Y, Ashcroft DM. The Safety of Delayed Versus Immediate Antibiotic Prescribing for Upper Respiratory Tract Infections. Clinical infectious diseases : an official publication of the Infectious Diseases Society of America. 2021;73(2):e394–e401. doi:10.1093/cid/ciaa890 32594104
12 Jindai K, Itaya T, Ogawa Y, . Decline in oral antimicrobial prescription in the outpatient setting after nationwide implementation of financial incentives and provider education: An interrupted time-series analysis. Infection control and hospital epidemiology. 2023;44(2):253–259. doi:10.1017/ice.2022.49 35382915
13 Sato D, Goto T, Uda K, Kumazawa R, Matsui H, Yasunaga H. Impact of national guidelines for antimicrobial stewardship to reduce antibiotic use in upper respiratory tract infection and gastroenteritis. Infection control and hospital epidemiology. 2021;42(3):280–286. doi:10.1017/ice.2020.427 32959738
14 Feldmeier G, Loffler C, Altiner A, . Optimizing Antibiotic Prescribing for Acute Respiratory Tract Infections in German Primary Care: Results of the Regional Intervention Study CHANGE-3 and the Nested cRCT. Antibiotics. 2023;12(5):850. doi:10.3390/antibiotics12050850 37237753
15 McNulty C, Hawking M, Lecky D, . Effects of primary care antimicrobial stewardship outreach on antibiotic use by general practice staff: pragmatic randomized controlled trial of the TARGET antibiotics workshop. The Journal of antimicrobial chemotherapy. 2018;73(5):1423–1432. doi:10.1093/jac/dky004 29514268
16 McIsaac W, Kukan S, Huszti E, . A pragmatic randomized trial of a primary care antimicrobial stewardship intervention in Ontario, Canada. BMC family practice. 2021;22(1):185. doi:10.1186/s12875-021-01536-3 34525972
17 Australia BERT-Go, Government BETotA. Nudge vs Superbugs: A behavioural economics trial to reduce the overprescribing of antibiotics. Commonwealth of Australia Canberra, ACT; 2018.
18 Tonkin-Crine S, McLeod M, Borek AJ, . Implementing antibiotic stewardship in high-prescribing English general practices: a mixed-methods study. British Journal of General Practice. 2023;73(728):E164–E175. doi:10.3399/BJGP.2022.0298
19 Llor C, Bjerrum L, Molero JM, . Long-term effect of a practice-based intervention (HAPPY AUDIT) aimed at reducing antibiotic prescribing in patients with respiratory tract infections. Journal of Antimicrobial Chemotherapy. 2018;73(8):2215–2222. doi:10.1093/jac/dky137 29718420
20 Schwartz KL, Shuldiner J, Langford BJ, . Mailed feedback to primary care physicians on antibiotic prescribing for patients aged 65 years and older: Pragmatic, factorial randomised controlled trial. BMJ. 2024:e079329. doi:10.1136/bmj-2024-079329 38839101
21 Soucy JPR, Low M, Acharya KR, . Evaluation of an automated feedback intervention to improve antibiotic prescribing among primary care physicians (OPEN Stewardship): a multinational controlled interrupted time-series study. Microbiology Spectrum. 2024;12(4)doi:10.1128/spectrum.00017-24
22 Guo RF, Nguyen DL, Park S, . Practitioner Education and Feedback to Decrease Ciprofloxacin Prescriptions in Patients with Acute Uncomplicated Cystitis. The Permanente journal. 2020;24doi:10.7812/TPP/18.036
23 Schwartz KL, Ivers N, Langford BJ, . Effect of Antibiotic-Prescribing Feedback to High-Volume Primary Care Physicians on Number of Antibiotic Prescriptions: A Randomized Clinical Trial. JAMA Internal Medicine. 2021;181(9):1165–1173. doi:10.1001/jamainternmed.2021.2790 34228086
24 Milani RV, Wilt JK, Entwisle J, Hand J, Cazabon P, Bohan JG. Reducing inappropriate outpatient antibiotic prescribing: normative comparison using unblinded provider reports. BMJ open quality. 2019;8(1):e000351. doi:10.1136/bmjoq-2018-000351
25 Hemkens LG, Saccilotto R, Reyes SL, . Personalized prescription feedback using routinely collected data to reduce antibiotic use in primary care a randomized clinical trial. JAMA Internal Medicine. 2017;177(2):176–183. doi:10.1001/jamainternmed.2016.8040 28027333
26 van der Velden AW, Kuyvenhoven MM, Verheij TJM. Improving antibiotic prescribing quality by an intervention embedded in the primary care practice accreditation: The ARTI4 randomized trial. Journal of Antimicrobial Chemotherapy. 2016;71(1):257–263. doi:10.1093/jac/dkv328 26490015
27 Hurlimann D, Limacher A, Schabel M, . Improvement of antibiotic prescription in outpatient care: A cluster-randomized intervention study using a sentinel surveillance network of physicians. Journal of Antimicrobial Chemotherapy. 2015;70(2):602–608. doi:10.1093/jac/dku394 25326088
28 Schmiemann G, Greser A, Maun A, . Effects of a multimodal intervention in primary care to reduce second line antibiotic prescriptions for urinary tract infections in women: parallel, cluster randomised, controlled trial. BMJ (Clinical research ed). 2023;383:e076305. Comment in: BMJ. 2023 Dec 15;383:2841 PMID: 38101928 [https://www.ncbi.nlm.nih.gov/pubmed/38101928]. doi:10.1136/bmj-2023-076305
29 Carney G, Maclure M, Patrick DM, . A cluster randomized trial assessing the impact of personalized prescribing feedback on antibiotic prescribing for uncomplicated acute cystitis to family physicians. PloS one. 2023;18(7):e0280096. doi:10.1371/journal.pone.0280096 37523381
30 Jones GF, Fabre V, Hinson J, . Improving antimicrobial prescribing for upper respiratory infections in the emergency department: Implementation of peer comparison with behavioral feedback. Antimicrobial stewardship & healthcare epidemiology : ASHE. 2021;1(1):e70. doi:10.1017/ash.2021.240 36168488
31 Livorsi DJ, Nair R, Dysangco A, . Using Audit and Feedback to Improve Antimicrobial Prescribing in Emergency Departments: A Multicenter Quasi-Experimental Study in the Veterans Health Administration. Open forum infectious diseases. 2021;8(6):ofab186. doi:10.1093/ofid/ofab186 34113685
32 Aghlmandi S, Halbeisen FS, Saccilotto R, . Effect of Antibiotic Prescription Audit and Feedback on Antibiotic Prescribing in Primary Care: A Randomized Clinical Trial. JAMA internal medicine. 2023;183(3):213–220. Comment in: JAMA Intern Med. 2023 Mar 1;183(3):220-222 PMID: 36877210 [https://www.ncbi.nlm.nih.gov/pubmed/36877210]. doi:10.1001/jamainternmed.2022.6529 36745412
33 Singer A, Kosowan L, Abrams EM, . Implementing an audit and feedback cycle to improve adherence to the Choosing Wisely Canada recommendations: clustered randomized trail. BMC primary care. 2022;23(1):302. doi:10.1186/s12875-022-01912-7 36435746
34 Marwick CA, Hossain A, Nogueira R, . Feedback of Antibiotic Prescribing in Primary Care (FAPPC) trial: results of a real-world cluster randomized controlled trial in Scotland, UK. The Journal of antimicrobial chemotherapy. 2022;77(12):3291–3300. doi:10.1093/jac/dkac317 36172861
35 Gold N, Sallis A, Saei A, . Using text and charts to provide social norm feedback to general practices with high overall and high broad-spectrum antibiotic prescribing: a series of national randomised controlled trials. Trials. 2022;23(1):511. doi:10.1186/s13063-022-06373-y 35717262
36 Grigoryan L, Zoorob R, Germanos G, . Case-based audit and feedback around a decision aid improved antibiotic choice and duration for uncomplicated cystitis in primary care clinics. Family medicine and community health. 2021;9(3)doi:10.1136/fmch-2020-000834
37 Curtis HJ, Bacon S, Croker R, . Evaluating the impact of a very low-cost intervention to increase practices’ engagement with data and change prescribing behaviour: a randomized trial in English primary care. Family practice. 2021;38(4):373–380. doi:10.1093/fampra/cmaa128 33783497
38 Madaras-Kelly K, Hostler C, Townsend M, . Impact of Implementation of the Core Elements of Outpatient Antibiotic Stewardship Within Veterans Health Administration Emergency Departments and Primary Care Clinics on Antibiotic Prescribing and Patient Outcomes. Clinical infectious diseases : an official publication of the Infectious Diseases Society of America. 2021;73(5):e1126–e1134. doi:10.1093/cid/ciaa1831 33289028
39 Du Yan L, Dean K, Park D, . Education vs Clinician Feedback on Antibiotic Prescriptions for Acute Respiratory Infections in Telemedicine: a Randomized Controlled Trial. Journal of general internal medicine. 2021;36(2):305–312. doi:10.1007/s11606-020-06134-0 32845446
40 Ratajczak M, Gold N, Hailstone S, Chadborn T. The effectiveness of repeating a social norm feedback intervention to high prescribers of antibiotics in general practice: a national regression discontinuity design. The Journal of antimicrobial chemotherapy. 2019;74(12):3603–3610. doi:10.1093/jac/dkz392 31539423
41 Gulliford MC, Juszczyk D, Prevost AT, . Electronically delivered interventions to reduce antibiotic prescribing for respiratory infections in primary care: Cluster RCT using electronic health records and cohort study. Health Technology Assessment. 2019;23(11):1–72. doi:10.3310/hta23110
42 Dutcher L, Degnan K, Adu-Gyamfi AB, . Improving Outpatient Antibiotic Prescribing for Respiratory Tract Infections in Primary Care: A Stepped-Wedge Cluster Randomized Trial. Clinical infectious diseases : an official publication of the Infectious Diseases Society of America. 2022;74(6):947–956. doi:10.1093/cid/ciab602 34212177
43 Dean NC, Vines CG, Carr JR, . A Pragmatic, Stepped-Wedge, Cluster-controlled Clinical Trial of Real-Time Pneumonia Clinical Decision Support. American Journal of Respiratory and Critical Care Medicine. 2022;205(11):1330–1336. doi:10.1164/rccm.202109-2092OC 35258444
44 McGinn TG, McCullagh L, Kannry J, . Efficacy of an evidence-based clinical decision support in primary care practices: A randomized clinical trial. JAMA Internal Medicine. 2013;173(17):1584–1591. doi:10.1001/jamainternmed.2013.8980 23896675
45 Dean NC, Jones BE, Jones JP, . Impact of an electronic clinical decision support tool for emergency department patients with pneumonia. Annals of Emergency Medicine. 2015;66(5):511–520. doi:10.1016/j.annemergmed.2015.02.003 25725592
46 Gulliford MC, van Staa T, Dregan A, . Electronic health records for intervention research: a cluster randomized trial to reduce antibiotic prescribing in primary care (eCRT study). Annals of family medicine. 2014;12(4):344–351. doi:10.1370/afm.1659 25024243
47 Dezman ZDW, Lemkin D, Papier A, Browne B. The impact of a point-of-care visual clinical decision support tool on admissions for cellulitis in the University of Maryland medical system. Journal of the American College of Emergency Physicians open. 2023;4(3):e12969. doi:10.1002/emp2.12969 37304858
48 Mann D, Hess R, McGinn T, . Impact of Clinical Decision Support on Antibiotic Prescribing for Acute Respiratory Infections: a Cluster Randomized Implementation Trial. Journal of general internal medicine. 2020;35(Suppl 2):788–795. doi:10.1007/s11606-020-06096-3 32875505
49 May L, Nguyen MH, Trajano R, . A multifaceted intervention improves antibiotic stewardship for skin and soft tissues infections. American Journal of Emergency Medicine. 2021;46:374–381. doi:10.1016/j.ajem.2020.10.017 33139143
50 Mainous AG, Lambourne CA, Nietert PJ. Impact of a clinical decision support system on antibiotic prescribing for acute respiratory infections in primary care: Quasi-experimental trial. Journal of the American Medical Informatics Association. 2013;20(2):317–324. doi:10.1136/amiajnl-2011-000701 22759620
51 Gjelstad S, Hoye S, Straand J, Brekke M, Dalen I, Lindbaek M. Improving antibiotic prescribing in acute respiratory tract infections: Cluster randomised trial from Norwegian general practice (prescription peer academic detailing (Rx-PAD) study). BMJ (Online). 2013;347(7920):f4403. doi:10.1136/bmj.f4403
52 Meeker D, Linder JA, Fox CR, . Effect of behavioral interventions on inappropriate antibiotic prescribing among primary care practices a randomized clinical trial. JAMA - Journal of the American Medical Association. 2016;315(6):562–570. doi:10.1001/jama.2016.0275 26864410
53 Persell SD, Doctor JN, Friedberg MW, . Behavioral interventions to reduce inappropriate antibiotic prescribing: A randomized pilot trial. BMC Infectious Diseases. 2016;16(1):373. doi:10.1186/s12879-016-1715-8 27495917
54 Gonzales R, Anderer T, McCulloch CE, . A cluster randomized trial of decision support strategies for reducing antibiotic use in acute bronchitis. JAMA Internal Medicine. 2013;173(4):267–273. doi:10.1001/jamainternmed.2013.1589 23319069
55 Hoye S, Gjelstad S, Lindbaek M. Effects on antibiotic dispensing rates of interventions to promote delayed prescribing for respiratory tract infections in primary care. British Journal of General Practice. 2013;63(616):e777–e786. doi:10.3399/bjgp13X674468
56 Vervloet M, Meulepas MA, Cals JWL, Eimers M, van der Hoek LS, van Dijk L. Reducing antibiotic prescriptions for respiratory tract infections in family practice: results of a cluster randomized controlled trial evaluating a multifaceted peer-group-based intervention. NPJ primary care respiratory medicine. 2016;26:15083. doi:10.1038/npjpcrm.2015.83
57 Vellinga A, Galvin S, Duane S, . Intervention to improve the quality of antimicrobial prescribing for urinary tract infection: A cluster randomized trial. CMAJ. 2016;188(2):108–115. doi:10.1503/cmaj.150601 26573754
58 Colliers A, Coenen S, Teughels S, . Improving antibiotic prescribing quality in out-of-hours primary care: a mixed-methods study using participatory action research. JAC-antimicrobial resistance. 2023;5(6):dlad131. doi:10.1093/jacamr/dlad131 38089462
59 Poss-Doering R, Kronsteiner D, Kamradt M, . Assessing reduction of antibiotic prescribing for acute, non-complicated infections in primary care in germany: Multi-step outcome evaluation in the cluster-randomized trial arena. Antibiotics. 2021;10(10):1151. doi:10.3390/antibiotics10101151 34680732
60 Nguyen HM, Flerchinger S, Smith JR, Felcher AH, Turley M, McNamara M. Diagnostic and antibiotic stewardship lessons: an outpatient assessment of symptomatic reflex urinalysis ordering accuracy using an electronic best-practice alert. The Journal of antimicrobial chemotherapy. 2023;78(9):2283–2290. doi:10.1093/jac/dkad233 37492974
61 Poss-Doering R, Kuhn L, Kamradt M, . Fostering Appropriate Antibiotic Use in a Complex Intervention: Mixed-Methods Process Evaluation Alongside the Cluster-Randomized Trial ARena. Antibiotics (Basel, Switzerland). 2020;9(12)doi:10.3390/antibiotics9120878
62 Poss-Doering R, Kuehn L, Kamradt M, Glassen K, Wensing M. Applying digital information delivery to convert habits of antibiotic use in primary care in Germany: Mixed-methods study. Journal of Medical Internet Research. 2020;22(10):e18200. doi:10.2196/18200 32960773
63 Rodrigues DM, Petersen RL, de Moraes JR, Barboza EP. Gingival landmarks and cutting points for gingival phenotype determination: A clinical and tomographic cross-sectional study. Journal of Periodontology. 2022;93(12):1916–1928. doi:10.1002/JPER.21-0615 35451505
64 Poss-Doering R, Kuehn L, Kamradt M, . Converting habits of antibiotic use for respiratory tract infections in German primary care (CHANGE-3) - process evaluation of a complex intervention. BMC family practice. 2020;21(1):274. doi:10.1186/s12875-020-01351-2 33341114
65 Colquhoun HL, Brehaut JC, Sales A, . A systematic review of the use of theory in randomized controlled trials of audit and feedback. Implementation Science. 2013/06/10 2013;8(1):66. doi:10.1186/1748-5908-8-66 23759034
66 Sarkies M, Francis-Auton E, Long J, . Audit and feedback to reduce unwarranted clinical variation at scale: a realist study of implementation strategy mechanisms. Implementation Science. 2023/12/11 2023;18(1):71. doi:10.1186/s13012-023-01324-w 38082301
67 Xu AXT, Brown K, Schwartz KL, . Audit and Feedback Interventions for Antibiotic Prescribing in Primary Care: A Systematic Review and Meta-analysis. Clinical Infectious Diseases. 2025;80(2):253–262. doi:10.1093/cid/ciae604 39657007
68 Xu R, Wu L, Xu C, Mu T. Effectiveness of decision support tools on reducing antibiotic use for respiratory tract infections: a systematic review and meta-analysis. Frontiers in Pharmacology. 2023;14:1253520. doi:10.3389/fphar.2023.1253520 37745052
69 Lauri Hicks DotOoAS, CDC. In: ESP MV, editor. 2025.