# ACKNOWLEDGMENTS

The authors are grateful to Amy Claussen, MLIS for expertise and execution of the literature search for this review. We also thank Dr. Lauri Hicks, Director of the Office of Antibiotic Stewardship at the Centers for Disease Control and Prevention (CDC), who provided initial feedback on the scope, key questions, and protocol for this review.

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Daniel Livorsi, MD, MSc
  VA National Antimicrobial Stewardship Taskforce
  Medical Director of Antimicrobial Stewardship
  Iowa City VA Health Care System

- Allison Kelly, MD
  Physician, VHA National Infectious Diseases Service
  Cincinnati VA Medical Center

- Stephen Kralovic, MD, MPH
  Physician, VHA National Infectious Diseases Service
  Cincinnati VA Medical Center

- Kelly Echevarria, PharmD
  National Clinical Pharmacy Program Manager for Infectious Diseases
  Department of Veterans Affairs

- Karl Madaras-Kelly, PharmD, MPH
  VA National Antimicrobial Stewardship Taskforce
  Pharmacist
  Boise VA Medical Center

## Technical Expert Panel

To ensure robust, scientifically relevant work, the technical expert panel (TEP) guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members included:

- Deanna Buehrle, PharmD
  Clinical Pharmacist
  Pittsburgh VA Medical Center

- Michael Ward, MD, PhD
  Emergency Department Staff Physician
  VA Tennessee Valley Health Care System

- Jeffrey Linder, MD, MPH, FACP
  Chief, Division of General Internal Medicine, Michael A. Gertz Professor of Medicine
  Northwestern University Feinberg School of Medicine

- Barbara E. Jones, MD, MSCI
  Associate Professor, Division of Pulmonary Medicine, Department of Medicine
  University of Utah

## Key Informants

The ESP sought input from key informants with diverse experiences and perspectives relevant to the review topic. Key informants included:

- Allison Gustavson, PT, DPT, PhD
  Associate Professor of Medicine, Division of General Internal Medicine, University of Minnesota Core Investigator, Center for Care Delivery and Outcomes Research (CCDOR)
  Minneapolis VA Health Care System