# Executive Summary

KEY FINDINGS

### Key Question 1 What are the characteristics of studies that have evaluated antimicrobial stewardship programs or strategies focused on improving antimicrobial prescribing?

► Updated evidence base (since 2013) includes 285 unique primary studies and 37 systematic reviews addressing outpatient antimicrobial stewardship.
► Studies evaluating education only or with audit and feedback dominate the evidence base.
► Most studies were conducted in either emergency room (ER)/urgent care or primary care settings, with less evidence in other outpatient settings.
► Studies were mostly observational (k = 226, 79%), with only a fifth of these including concurrent comparators.
► Overall antimicrobial and inappropriate (or appropriate) prescribing rates were the most frequently reported outcomes; patient treatment outcomes and health care utilization were also commonly reported (k = 109, 39%).
► Few studies assessed staff satisfaction and acceptability, implementation costs and barriers, sustainability, or reach.

### Key Question 2 For prioritized studies (based on settings and type of programs or strategies), what are the reported outcomes associated with implementation of antimicrobial stewardship programs or strategies?

► Forty-five prioritized studies evaluated audit and feedback (k = 25, 57%), clinical decision support systems (CDSS, k = 6, 12%), or multicomponent stewardship programs (k = 14, 32%), in ER and/or primary care settings; these were all randomized controlled trials (k = 29, 66%) or observational studies with concurrent comparators.
► Half of studies were conducted in Europe (k = 21, 50%); a substantial number occurred in national or regional health systems (k = 19, 43%), including 2 in Veterans Health Administration.
► Audit and feedback approaches varied, with differences in feedback frequency, reference groups (for comparing prescribing rates), and delivery formats.
► CDSS tools predominantly involved clinician education or antimicrobial recommendations; fewer incorporated order sets that would improve clinician workflow.
► Audit and feedback and CDSS were the most frequently employed strategies (with or without education and other additional strategies) in multicomponent stewardship programs.
► Audit and feedback, CDSS, and multicomponent programs did not consistently reduce overall or inappropriate antimicrobial prescribing; synthesis was limited by substantial variation across studies.
► A quarter of studies assessed patient treatment outcomes and/or health care utilization (k = 12); there were no differences between groups in most patient outcomes.
► Few studies evaluated implementation costs and/or barriers, staff satisfaction and acceptability, or reach.
► No study addressed changes in microbial resistance patterns.

Antimicrobial stewardship programs (ASP) seek to improve antimicrobial prescribing practices, optimize patient outcomes, and reduce antimicrobial resistance. For patients, more appropriate prescribing should lead to lower morbidity and mortality from infectious conditions and fewer adverse events related to antimicrobial overuse. For communities, better prescribing can prevent higher levels of antimicrobial resistance, which is currently estimated to cause 5 million additional deaths per year globally. Growing antimicrobial resistance, such as increasing occurrence of extended spectrum beta lactamase (ESBL) expression in gram-negative bacteria, leaves patients with fewer antimicrobial options, increased drug toxicity, and increased mortality.

More than 80% of antimicrobial usage occurs in the outpatient setting, including primary care clinics, dental clinics, emergency rooms (ER), urgent care, and other sites. Furthermore, nearly 30% of antibiotics prescribed in the outpatient setting may be inappropriate or unnecessary. Outpatient ASPs have unique challenges, including the need to tailor strategies for clinics with varying resources and a diversity of clinical populations. Similar to other efforts to improve clinical practice, specific barriers to change also include patient expectations and priorities, decreasing time for clinical visits, and greater administrative burden for clinicians. Understanding which strategies have been effective and the implementation process for these will be critical for optimizing ASPs and planning future implementation efforts.

The Centers for Disease Control and Prevention (CDC) have outlined 4 core elements of outpatient antibiotic stewardship (commitment by clinicians and health care leadership, action through implementation of at least 1 policy or practice, tracking of prescribing and feedback of these data to prescribers, and patient and clinician education on appropriate antimicrobial prescribing). It is currently unclear if outpatient ASPs with all of these core elements would be more successful at improving antimicrobial prescribing practices. Additionally, specific strategies may be more impactful when used alone or in combination with other strategies within an ASP.

## CURRENT REVIEW

To inform efforts to implement and improve outpatient ASP for VHA clinics and facilities, the VA National Antimicrobial Stewardship Taskforce and the VHA National Infectious Disease Service requested an update to the prior evidence review conducted by the VA Evidence Synthesis Program in 2013. We conducted an evidence map to describe evidence (published since 2013) on the effects and implementation processes of ASP strategies and programs in outpatient settings. We also completed a systematic review of a prioritized set of eligible studies that were conducted in primary care and/or ER settings.

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (CRD42024603377 (https://www.crd.york.ac.uk/PROSPERO/view/CRD42024603377)). Key questions of this review are noted above in the Key Findings section.

Medline, Embase, and Scopus were searched from January 1, 2013–September 3, 2024, using terms for antimicrobial prescribing, drug resistance, guideline adherence, evaluation, and specific strategies (eg, audit and feedback). Abstracts were screened in 2 phases, with the assistance of DistillerSR’s Artificial Intelligence System (DAISY). In the first phase, abstracts were excluded only if 2 independent reviewers agreed on exclusion; 10,441 abstracts were screened, until the remaining studies had predicted likelihood for inclusion ≤ 0.1. In the second phase, a single human reviewer screened an additional 6,368 abstracts for inclusion; no eligible article was identified during this additional screening. The remaining 43% of abstracts (12,729) were not examined by a human reviewer. DAISY predictions indicated we may have missed 4 articles for inclusion by not further reviewing the remaining abstracts. Full-text review was completed by 2 individuals with limited extraction of study characteristics; reviewers had to agree on inclusion and reconcile extraction before the article was included in the evidence map.

For the evidence map, we abstracted study design, population, setting, intervention, and reported outcomes. For prioritized studies, we abstracted effect information and population, intervention and comparator characteristics. We conducted risk of bias using the Cochrane ROB 2.0 and Newcastle Ottawa tools. All data abstraction was completed by 1 reviewer and overread by an independent reviewer, disagreements were resolved by consensus or discussion with a third reviewer.

We completed meta-analyses for findings in prioritized studies if there were ≥ 3 studies that evaluated an outcome in a similar manner and the reported effect measure was conducive to the analysis. If we were unable to pool the evidence, we present the data in a narrative summary. We did not rate the certainty of evidence for this review.

### Evidence Map Results

From 29,544 unique citations/abstracts, we identified 285 primary studies (reported in 322 articles) and 37 systematic reviews. The majority of primary studies were observational (k = 226), including 41 with contemporaneous comparators, and 59 were RCTs. A quarter of studies were conducted at a single site (k = 69), a fifth included 2–10 sites (k = 53), and less than a tenth included more than 100 sites (k = 25); these latter studies took place in very large health systems and/or across large geographic areas (eg, involving regional or national health systems or networks).

We categorized primary studies by antimicrobial stewardship strategies and programs. These specific strategies were: 1) audit and feedback, 2) clinical decision support systems (CDSS) embedded in electronic health record (EHR) systems, 3) laboratory tests, 4) pharmacist review, 5) public health campaigns, 6) delayed prescribing, 7) pay for performance, or 8) formulary policy changes. We also separately categorized studies examining multicomponent ASP that involved 2 or more of the specific strategies, usually in addition to patient and/or clinician education.

Across all settings, patient and/or clinician education only (k = 55), and audit and feedback (k = 48) were the most commonly evaluated individual strategies, while multicomponent stewardship programs were also frequently examined (k = 56). Somewhat fewer studies focused on CDSS (k = 35) or new laboratory testing (k = 45). Remaining studies evaluated public health campaigns (k = 22), pharmacist review (k = 15), delayed prescribing (k = 7), or pay for performance programs (k = 2).

ES Figure 1 Antimicrobial Stewardship Strategies Across Various Outpatient Settings

Notes. *Patient and/or clinician education.

^†^Tools embedded in electronic health records with computerized order entry.

^‡^Programs included 2 or more specific strategies, in addition to patient and/or clinician education.

^§^Nonspecific outpatient setting or multiple types of outpatient clinics (eg, primary care and medical specialties).

#### Primary Care Studies (k = 151)

- One hundred three studies were observational (one-fifth including a concurrent comparator), and 48 were RCTs.
- Audit and feedback was the most frequently evaluated (k = 35), followed by multicomponent ASPs (k = 32), and patient/clinician education alone (k = 27).
- For multicomponent ASPs, the most common combination was audit and feedback with CDSS (k = 17).
- Overall antimicrobial prescribing was frequently reported (k = 123), and inappropriate or appropriate antimicrobial prescribing was reported less often (k = 53).
- Less than a quarter evaluated patient treatment outcomes (eg, acceptability, satisfaction, infections successfully treated, and adverse events, k = 33) or health care utilization (k = 25), or staff satisfaction (k = 21).

#### Emergency Room/Urgent Care Studies (k = 95)

- Eighty-seven studies were observational (14 with concurrent comparators) and 8 were RCTs.
- Algorithms with laboratory tests (k = 21) followed by multicomponent programs were the most commonly investigated strategies.
- Nearly all studies were small (88% with 10 sites or less) and only 2 included more than 100 sites.
- Change in overall antimicrobial prescribing (k = 76), inappropriate or appropriate prescribing (k = 49), and patient health care utilization (k = 42) were the most frequently reported outcomes.

ES Figure 2 Primary Care and Emergency Room/Urgent Care Studies: Outcomes Reported for Various Antimicrobial Stewardship Strategies and Programs

Notes. *Patient and/or clinician education.

^†^Tools embedded in electronic health records with computerized order entry.

^‡^Programs included 2 or more specific strategies, in addition to patient and/or clinician education.

^§^Long-term effects on antimicrobial prescribing, at least 1 year after (and in a separate phase from) initial implementation.

A heatmap of the included primary studies in primary care and emergency room/urgent care settings plotted by the type of intervention or strategy implemented and outcomes measured. Strategies were grouped as: patient and/or clinician education only, audit and feedback, clinical decision support system, laboratory test, pharmacist review, delayed prescribing, pay for performance, public health campaigns, and multicomponent programs which included 2 or more specific strategies in addition to patient and/or clinician education. Outcomes measured included overall antimicrobial prescribing, appropriate or inappropriate prescribing, sustainability, patient treatment outcomes, patient healthcare utilization, microbial resistance, staff satisfaction, implementation costs, other barriers and facilitators, maintenance costs, reach patients, reach prescribers & clinics. The highest concentration of studies by outcomes measured in primary care setting were overall antimicrobial prescribing in education only, audit and feedback, and multicomponent programs strategies. The highest concentration of studies by outcomes measured in emergency room/urgent care setting were overall prescribing and appropriate or inappropriate prescribing in audit and feedback, clinical decision support system, laboratory test, and multicomponent programs.

#### Other Outpatient Settings (k = 58)

- Studies were conducted in non-specified outpatient or multiple clinic settings (k = 36), outpatient pharmacy (k = 11), dental clinic (k = 6), outpatient surgery (k = 4), and dialysis facilities (k = 1).
- Fifty-four were observational, 7 of which had concurrent comparators, and 4 were RCTs.
- Patient/clinician education alone (k = 13), CDSS (k = 11), multicomponent (k = 10), and public health campaigns (k = 9) were the most commonly evaluated ASPs or strategies.
- Change in antimicrobial prescribing was the most frequently reported outcome (k = 48), followed by inappropriate or appropriate prescribing (k = 18).

#### Eligible Systematic Reviews

The 37 eligible systematic reviews included 10–59 primary studies conducted in a range of settings, including primary care (k = 17), ER/urgent care (k = 5), general outpatient (k = 5), outpatient pharmacy (k = 2), and dental clinics (k = 1). There were also 7 reviews that included studies covering multiple settings. Reviews included studies that examined a range of antimicrobial stewardship strategies and multicomponent programs, with education only, audit and feedback, CDSS, and laboratory tests being the most common. Eligible reviews most often addressed antimicrobial prescribing (k = 34), followed by patient treatment outcomes (k = 20) and health care utilization (k = 12). Ten reviews examined inappropriate or appropriate prescribing, and few addressed implementation costs (k = 4) or other barriers and facilitators (k = 3), staff satisfaction (k = 2), changes in microbial resistance (k = 1), or maintenance costs (k = 1).

### Systematic Review of Prioritized Studies (k = 45)

For detailed findings on eligible outcomes and synthesis of results, we prioritized studies that were conducted in primary care and/or ER setting; investigated audit and feedback, EHR-based CDSS, or multicomponent ASPs, and either an RCT (k = 29) or an observational study with at least 1 concurrent comparator (k = 16). Study characteristics are briefly discussed before results for individual outcomes are presented. No prioritized study reported on sustainability, microbial resistance patterns, or reach among patients and communities.

#### Prioritized Study Characteristics

##### Audit and Feedback (k = 25)

All 25 studies evaluating audit and feedback also included patient and/or clinician education, and 2 of these studies occurred during an ongoing public health campaign. The frequency and format of feedback varied across studies, with 14 using at least 2 rounds of feedback. The reference groups for peer comparisons included other prescribers in the same clinic, regional or national clinicians, and the top 20% of performers. Most studies assessed change in overall antimicrobial use and/or inappropriate or appropriate prescribing. Patient treatment outcomes and health care utilization were reported less frequently.

##### CDSS (k = 6)

Six studies compared CDSS with usual care; 4 were RCTs and 2 were observational. All studies were activated when certain criteria were met in EHR, and provided clinician education on diagnosis and/or antimicrobial prescribing. Fewer incorporated order sets for next steps in care. Overall antimicrobial use and inappropriate prescribing were the most commonly reported outcomes. Patient treatment outcomes and health care utilization were addressed by fewer studies.

##### Multicomponent ASPs (k = 14)

Fourteen studies evaluated multicomponent ASPs, with 10 of these using a combination of audit and feedback with CDSS in at least 1 arm; some studies also used additional strategies (eg, laboratory test or delayed prescribing). Five of these focused primarily on comparing combined audit and feedback and CDSS versus usual care or clinician education, with 2 also including different versions of CDSS in separate arms. The 3 remaining studies examined combined audit and feedback and C-reactive protein (CRP) testing, CRP testing with delayed prescribing, and audit and feedback with delayed prescribing, respectively. Overall antimicrobial use and inappropriate prescribing were the most frequently reported outcomes. Patient treatment outcomes and health care utilization were rarely addressed.

#### Impact of Prioritized Strategies and Multicomponent ASPs on Antimicrobial Prescribing

##### Overall Antimicrobial Use

Twenty-two studies compared the effect of audit and feedback versus usual care on overall antimicrobial prescribing. Data from 8 studies were included in a quantitative meta-analysis; these studies all assessed changes in overall antimicrobial prescribing ≥ 12 months after implementation, were general in scope or focused on respiratory conditions, and reported the effect measures appropriate for meta-analysis. The pooled estimate was RR = 0.89, 95% CI [0.77, 1.03], indicating no differences comparing audit and feedback versus usual care at the latest follow-up time point; there was high heterogeneity. Studies not contributing data to the meta-analysis included 3 studies that focused solely on increasing or decreasing the use of specific antibiotics, and 11 that did not report data amenable for analysis (eg, only mean or median prescribing rates across practices, model estimated rates, or between-group differences in rates or change in rates pre-post implementation). There was inconsistency in the size, direction, and significance of effect reported by these 11 studies.

Five studies compared CDSS versus usual care; 4 were RCTs (12–33 months) and 1 was observational (16 months). A meta-analysis was not done as studies varied substantially in focus of CDSS and definition of outcomes. Four studies focused on antimicrobial prescribing for respiratory tract infections, with 1 of these solely addressing antibiotic prescribing for pneumonia. The 4 studies examining CDSS for respiratory conditions showed inconsistent results. For example, 1 study found no difference in overall antibiotic prescription rates between CDSS and control groups, while another showed lower overall antibiotics in the CDSS arm; both of these studies implemented a similar CDSS tool for pneumonia and streptococcal pharyngitis. The fifth study used a photo-based differential to help clinicians with diagnosis and treatment of cellulitis and showed lower overall prescribing for patient visits where the tool had been activated.

Four studies evaluated the effects of combined audit and feedback and CDSS versus usual care on overall antimicrobial prescribing (as defined by authors, eg, percent of total visits with an antibiotic prescription, overall number of systemic oral antibiotic prescriptions per 1,000 patient visits, or mean number of antibiotic items per month) over 6-12 months, but we were unable to conduct meta-analysis due to lack of appropriate data reported by 1 study and the focus being substantially different in the single study on urinary tract infections. The 3 other studies all found that the ASP arms had higher overall prescribing rates after or during the study period, but in each study, the usual care group had lower baseline prescribing rates. Two of these reported greater reductions in overall prescribing when comparing the change over time between groups, and 1 indicated that the intervention group had lower odds of antibiotic prescriptions after adjustment for case-mix and patient demographics.

Two studies compared combined audit and feedback and CDSS with only audit and feedback and reported overall antimicrobial prescribing; both focused on respiratory infections. An RCT conducted with 156 Norwegian general practices found no differences between the combined program versus only audit and feedback. The second study was observational and included 3 general practice cooperatives in Belgium (total of 579 general practitioners). All 3 cooperatives carried out educational activities and audit and feedback, and 2 cooperatives also added EHR alerts or CRP testing, respectively. The cooperative implementing combined audit and feedback and EHR alerts was the only one to find a substantial change in rates (58%–43% post-implementation) but it also had the highest prescribing rates at baseline (28–47% for the other 2 cooperatives).

##### Inappropriate Prescribing

Fifteen studies evaluated inappropriate and/or appropriate prescribing for audit and feedback versus usual care. We included 5 studies in a meta-analysis; outcomes were examined at 12–21 months and defined as proportion of patient visits with antibiotics prescribed out of all visits that were categorized as inappropriate or unnecessary. Two studies were multi-arm evaluations of multicomponent ASPs but included audit and feedback versus usual care in 2 arms (out of 8 arms). There were no differences between groups in rates of inappropriate prescribing (pooled RR = 0.80, 95% CI [0.41, 1.57]) and there was high heterogeneity. Among studies not included in the meta-analysis, 3 focused on improving prescribing for urinary tract infections but definitions of appropriateness varied (2 solely by choice of antibiotic and 1 by choice and duration of antibiotics). Another study sought to increase specific antibiotics for urinary tract and respiratory infections, and to decrease fluoroquinolones for chronic lung disease. The remaining 6 studies not included in the meta-analysis all reported outcomes that were variably assessed and not amenable to pooling (eg, mean prescribing rates across practices, change in prescribing).

Five studies examined the effect of implementing a CDSS tool on inappropriate prescribing, compared with usual care. Three studies primarily addressed reduction of inappropriate prescribing for respiratory infections and were included in the meta-analysis; outcomes were examined at 12–33 months and defined as noted above for audit and feedback comparisons. Two of these studies evaluated multicomponent ASPs and also included arms with only CDSS versus usual care. There were no differences between groups in rates of inappropriate prescribing (pooled RR = 1.08, 95% CI [0.59, 1.97]). There was substantial heterogeneity in these studies. The 2 studies not included in the meta-analysis implemented a CDSS focused on increasing appropriate antimicrobial selection for pneumonia in the ER, including use of broad-spectrum antibiotics and coverage for resistant organisms.

Four RCTs compared combined audit and feedback and CDSS versus usual care and reported on inappropriate or appropriate antimicrobial prescribing. We were unable to conduct meta-analysis due to differences in the clinical focus and the duration of follow-up (2 studies with 6 months and 2 with 12–18 months). Two RCTs were conducted by the same group focused on respiratory infections, and used the same study design, consisting of 8 arms that compared all possible combinations of 3 strategies (audit and feedback, and 2 versions of CDSS) versus usual care. These RCTs reported inconsistent results, with one finding no differences in rates of inappropriate prescribing between the arms, and the other showing lower rates in the ASP arms. However, both studies reported that there were no significant synergies between strategies, after conducting adjusted hierarchical random effects models. The third RCT on respiratory infections included 3 arms comparing combined audit and feedback and CDSS versus only audit and feedback versus usual care; this study reported lower antimicrobial prescribing rates for acute bronchitis in the ASP group. The RCT addressing urinary tract infections found increased rates of prescribing for first-line antibiotics, but also higher overall rates for any antibiotic.

Three RCTs evaluated inappropriate antimicrobial prescribing for combined audit and feedback and CDSS versus audit and feedback only. Two of these were the same trials described above that included 8 arms examining all possible combinations of audit and feedback and 2 versions of CDSS. Both reported lower rates of inappropriate prescribing in the combined program groups versus audit and feedback alone, but in adjusted hierarchical models, there were no synergistic effects. The third RCT had 3 arms and was also described above; this reported no statistically significant differences between groups.

#### Impact of Prioritized Strategies and Multicomponent ASPs on Other Outcomes

##### Patient Treatment Outcomes and Health Care Utilization

Thirteen studies reported patient treatment outcomes (eg, adverse events) and/or health care utilization (eg, hospitalizations), and these primarily evaluated audit and feedback versus usual care (k = 7). Patient treatment outcomes included: infective complications, recurrent urinary tract infections, urosepsis, all-cause mortality, and adverse events. Studies generally found no differences in patient treatment outcomes between the intervention and comparator arms. For example, Livorsi, 2021 found no differences in all-cause mortality for audit and feedback versus usual care, and Madaras-Kelly, 2021 showed no differences in adverse events for audit and feedback versus usual care.

Measures of health care utilization included hospital admission, repeat emergency department visit, and all-cause hospitalization. All 9 studies that reported measures of health care utilization found no difference between the intervention and comparator arms. For example, Livorsi, 2021 found no between-group differences in repeat ER visits and inpatient admission at 12 months.

##### Staff Satisfaction and Acceptability

Five studies reported measures of staff satisfaction and acceptability; 3 evaluated audit and feedback while the other 2 studies addressed multicomponent ASPs. Four were conducted in Europe and the fifth in Canada. Authors surveyed participants regarding different components of the stewardship strategy or program, including the clinical and patient education aspects, audit and feedback, CDSS, and/or other components. Regarding audit and feedback, several studies reported that participants found the feedback to be useful. Two studies reported staff concerns regarding the increased time burden from additional tasks to perform. One of these studies also noted that reimbursements could impact adoption of certain components

##### Implementation Costs and Barriers

Two studies reported costs of antibiotics prescribed; both were RCTs comparing audit and feedback with usual care. One was conducted in Canada and the other in the UK. The Canadian study reported 6.1% reduction in costs associated with antibiotic prescriptions, in favor of audit and feedback. The UK study reported that there were no statistically significant differences, with the audit and feedback arm having 92% of costs in the usual care arm.

Four studies summarized themes on barriers and facilitators from surveys and interviews of participants; all were conducted in Europe. Three studies evaluated multicomponent ASPs. All studies included audit and feedback and clinician and patient education, and surveys and interviews mainly focused on these components. Consistent themes regarding the educational component of the antimicrobial stewardship strategies across the 4 studies included variable incorporation or engagement with educational components, increased competition for time and resources, and adaptability and flexibility of educational materials and formats.

##### Reach: Prescribers and Clinics

Five studies reported on reach among clinicians; 2 studies compared audit and feedback with usual care, and 3 studies evaluated CDSS. One study reported that access to dashboards (providing feedback) was similarly infrequent for both groups (25–26% of participants), and the other study noted variable uptake of clinician and patient educational materials (20–88%). Studies evaluating CDSS all assessed engagement with CDSS tools or alerts, with 2 finding low engagement (eg, 63 views per 1,000 visits for respiratory infections), and 1 reporting higher uptake (eg, completion of recommended order sets in 42% of applicable encounters).

## CONCLUSIONS

There has been substantial growth in the evidence base for antimicrobial stewardship in outpatient settings. Multicomponent ASPs, audit and feedback, and education alone were the most frequently evaluated. Audit and feedback, CDSS, or a combination of both did not consistently reduce overall antimicrobial use or inappropriate prescribing. Limited evidence indicates that these strategies and their combination did not impact patient treatment outcomes and health care utilization. There was little evidence on implementation cost or barriers, reach, or sustainability of ASPs or strategies. There remains an urgent need for effective strategies or multicomponent ASPs that can be implemented and sustained on a large scale in the outpatient setting.