# DISCUSSION

In this update to the previous ESP review on outpatient antimicrobial stewardship, we found that the body of evidence has grown significantly in size, with over 300 eligible studies identified.^5^ However, much of this evidence is observational and focused on education only or audit and feedback. Furthermore, detailed findings from the prioritized studies showed that audit and feedback, CDSS, or their combination in multicomponent ASPs did not have substantial impact on antimicrobial prescribing in the ER/urgent care and primary care settings. There was substantial variation in the characteristics of specific strategies (eg, audit and feedback) between studies, which likely contributed to the lack of consistent improvements in antimicrobial prescribing observed across the evidence base. Patient outcomes were less often reported than antimicrobial prescribing, but when assessed, there were generally no differences between groups.

## SUMMARY OF KEY FINDINGS

### Evidence Map

- Studies evaluating education only or with audit and feedback dominate the evidence base.
- Most studies were conducted in either ER/urgent care or primary care settings, with less evidence in other outpatient settings.
- Studies were mostly observational (k = 226, 79%), with only a fifth of these including concurrent comparators.
- Overall antimicrobial and inappropriate (or appropriate) prescribing rates were the most frequently reported outcomes.
- Patient treatment outcomes and health care utilization were also commonly reported (k = 143, 50%).
- Few studies assessed staff satisfaction and acceptability, implementation costs and barriers, sustainability, or reach.

### Prioritized Studies

- Most prioritized studies were RCTs (k = 29, 66%) and half were conducted in Europe (k = 21, 50%).
- A substantial number of studies were conducted in national or regional health systems (k = 19, 43%), including 2 in VHA.
- Audit and feedback approaches varied, with differences in feedback frequency, reference groups (for comparing prescribing rates), and delivery formats.
- CDSS tools predominantly involved clinician education or antimicrobial recommendations; fewer incorporated order sets that would improve clinician workflow.
- Among studies evaluating multicomponent ASPs, combined audit and feedback and CDSS were the most frequently employed strategies (with or without education and other additional strategies).
- Audit and feedback, CDSS, and multicomponent ASPs did not consistently reduce overall rates antimicrobial prescribing or decrease inappropriate prescribing.
- A quarter of studies assessed patient treatment outcomes and/or health care utilization (k = 12); there were no differences between groups in most outcomes.
- Few studies evaluated implementation costs and/or barriers, or staff satisfaction/acceptability.

Our results indicate that neither audit and feedback, CDSS, nor their combination in multicomponent ASPs led to consistent reductions in overall antimicrobial use or inappropriate prescribing in ER/urgent care or primary care settings. For prioritized studies evaluating audit and feedback, we were limited in the ability to synthesize the data due to variation in outcome measurement and reporting. We also noted substantial differences in feedback frequency and format, without an evident consensus across studies. Others have noted that audit and feedback should be based on specific behavioral theories and be presented in meaningful ways that engender confidence.^65,66^ But it remains unclear if there is an optimal frequency, format (eg, in person versus email), or reference group. For CDSS tools, most provided education and recommendations for diagnosis and treatment, but fewer included order sets to enable next steps in care; usability and acceptability were not often assessed. In general, studies did not address the potential barriers to implementation such as alert fatigue. When reported, engagement with CDSS tools was often low, thus limiting the impact of this strategy. Notably, the study reporting higher uptake of CDSS tool (eg, completion of recommended order sets in 42% of applicable encounters) did demonstrate lower overall antibiotic prescribing in the CDSS group.^44^

A recent systematic review of audit and feedback in primary care reported a reduction in overall antimicrobial prescribing (RR = 0.89, 95% CI [0.84, 0.95]) with high heterogeneity, based on a meta-analysis of 21 RCTs; it also found a similar reduction in inappropriate prescribing (RR = 0.77, 95% CI [0.68, 0.87]), using data from 16 RCTs.^67^ Our pooled estimates for overall and inappropriate antimicrobial prescribing was similar in magnitude (RR = 0.80-0.86) but large 95% CI covered effects in both directions for both analyses. Notably, Xu, 2025 included studies conducted in pediatric populations and nursing homes,^67^ which were not eligible groups and settings for the current review. A recent systematic review on CDSS for acute respiratory infections (in any setting) found a reduction in antimicrobial prescribing (RR = 0.90, 95% CI [0.85, 0.95]), but 5 pre-post studies and 11 RCTs were included in this meta-analysis.^68^ We were unable to conduct a meta-analysis for overall prescribing, and the pooled estimate for inappropriate prescribing favored usual care (although wide 95% CI covered effects in both directions).

## EVIDENCE GAPS AND FUTURE RESEARCH

The findings in this review are perhaps disappointing, particularly given that most prioritized studies followed the 4 core elements of outpatient antimicrobial stewardship recommended by the CDC (although leadership engagement and commitment was not explicitly described in many articles). However, the current core elements may help to establish the basic foundation for an effective ASP—necessary but not sufficient. The CDC is in the process of updating and expanding the core elements, in order to provide additional guidance on assessing specific outcome measures and to better support implementation and sustainability of future outpatient ASPs.^69^ Beyond adding 3 core elements (accountability, expertise, and reporting), the new guidance will also include more examples to guide operationalization in different outpatient settings. The goal is to offer both greater specificity and continued flexibility in adapting strategies and metrics to local priorities and resources. The updated core elements may also help inform outcome measures and components of ASPs evaluated in future studies.

Much of the available evidence included in this review focuses on the change in antimicrobial prescribing. Future research should address additional patient outcomes (eg, medication side effects from antimicrobials) implementation costs and barriers, staff satisfaction and acceptability, sustainability, and reach (patient and prescriber). Many of these outcomes would provide valuable insights to aid policy makers in decisions regarding the most feasible and appropriate strategies to implement in their health care systems. Additionally, studies are needed to better understand the optimal characteristics of audit and feedback and CDSS. For example, the frequency, reference groups, and format of feedback could be experimentally compared in a national or regional health care system with a sufficiently large number of outpatient clinics and facilities. For CDSS tools, the use of alerts and different types of order sets, along with frequency of interactions and timing within clinician workflows, are important characteristics that could be further examined in future studies. Ideally, changes in antimicrobial prescribing, patient treatment outcomes, and staff satisfaction and acceptability would all be evaluated.

## IMPLICATIONS FOR POLICY AND PRACTICE

Findings from the prioritized studies suggest that current stewardship strategies in the outpatient setting do not consistently result in significant reductions in either overall antimicrobial prescribing or inappropriate antimicrobial prescribing. Variable characteristics of audit and feedback and CDSS tools likely contributed to variation in the effect on antimicrobial prescribing. Since initiating outpatient ASPs is likely resource intensive, it may be helpful to set up centralized resources and/or toolboxes that guide local facilities in implementation efforts, including pre-implementation assessments and process measures during implementation. Large national and regional health care systems may also consider environmental scans to better understand current stewardship practices and challenges.

## LIMITATIONS

We identified and critically appraised a large body of evidence evaluating the implementation of ASPs and strategies in a variety of outpatient settings. Due to the broad scope, we conducted an evidence map and then prioritized specific ASPs and strategies (in addition to settings and study designs) for full assessment and synthesis of detailed findings. The evidence map describes the characteristics of existing research and highlights gaps in certain areas. However, we did not assess or conduct detailed data abstraction or synthesis for studies in non-prioritized settings or strategies. We limited our search to English-language studies and reviews; we may have missed relevant publications in non-English languages.

## CONCLUSIONS

There has been substantial growth in the evidence base for antimicrobial stewardship in outpatient settings. Multicomponent ASPs, audit and feedback, and education alone were the most frequently evaluated. Audit and feedback, CDSS, or a combination of both did not consistently reduce overall antimicrobial use or inappropriate prescribing. Limited evidence indicates that these strategies and their combination did not impact patient treatment outcomes and health care utilization. There was little evidence on implementation cost or barriers, reach, or sustainability of ASPs or strategies. There remains an urgent need for effective strategies or multicomponent ASPs that can be implemented and sustained on a large scale in the outpatient setting.