# RESULTS

## LITERATURE OVERVIEW

Figure 2 Literature Flow Diagram

The literature flow diagram summarizes the results of the study selection process. A full list of excluded studies is provided in the Supplementary Materials.

Literature flow diagram summarizing results of study selection process.

Below, we first present an evidence map of eligible primary studies and systematic reviews. We then provided detailed findings and syntheses of results from the set of prioritized studies, namely comparative observational studies or RCTs which evaluated audit and feedback, CDSS, or multicomponent ASPs in primary care and ER/urgent care.

## EVIDENCE MAP OF ELIGIBLE PRIMARY STUDIES AND SYSTEMATIC REVIEWS

From 29,544 unique citations/abstracts, we identified 285 primary studies (reported in 322 articles) and 37 systematic reviews, for a total of 341 included studies (see Figure 2). The majority of eligible primary studies were observational (k = 226), including 41 with contemporaneous comparators, and 59 were RCTs. A quarter of studies were conducted at a single site (k = 69), a fifth included 2–10 sites (k = 53), and less than a tenth included more than 100 sites (k = 25; Figure 3); these latter studies took place in very large health systems and/or across large geographic areas (eg, involving regional or national health systems or networks).

Figure 3 Number of Clinic Sites Included by Primary Studies

Bar plot summarizing the number of primary studies by the number of sites in which the intervention was conducted. The number of clinic sites was categorized as follows: a single site, 2-10 sites, 11-50 sites, 51-100 sites, 101-200 sites, or more than 200 sites.

Most primary studies were conducted in primary care (k = 135) or ER/urgent care settings (k = 79). A smaller number of studies evaluated ASPs or strategies in non-specific outpatient settings (k = 32) or across multiple settings (k = 18), with all those in this latter group including sites in primary care and/or ER/urgent care. Fewer studies were conducted in outpatient pharmacy (k = 10), outpatient surgery (k = 4), dental clinics (k = 6), or outpatient dialysis (k = 1).

Across all eligible primary studies, the most commonly evaluated individual strategies were patient and/or clinician education only (k = 55), audit and feedback (k = 48), and laboratory testing (k = 45); multicomponent ASPs were also frequently examined (k = 56). Fewer studies specifically focused on CDSS (k = 35), public health campaigns (k = 22), pharmacist review (k = 15), delayed prescribing (k = 7), or pay for performance programs (k = 2).

There were generally similar patterns for frequency of ASPs or strategies being examined across different outpatient settings (Figure 4). For example, studies in primary care settings most commonly utilized education only, audit and feedback, or multicomponent programs. However, there were some differences across settings, such as the relatively greater number of studies focused on new laboratory tests (as opposed to other specific strategies) in the ER/urgent care settings. Studies evaluating public health campaigns occurred mainly in primary care and general nonspecific outpatient settings. Below, we first describe the characteristics of eligible primary studies conducted in primary care settings, followed by those that took place in ER/ urgent care, and then in a variety of remaining outpatient settings. Lastly, we summarize characteristics of eligible systematic reviews.

Figure 4 Antimicrobial Stewardship Strategies Across Various Outpatient Settings

Notes. *Patient and/or clinician education

^†^Tools embedded in electronic health records with computerized order entry.

^‡^Programs included 2 or more specific strategies, in addition to patient and/or clinician education.

^§^Non-specific outpatient setting or multiple types of outpatient clinics (eg, primary care and medical specialties).

A heatmap of the included primary studies depicting the settings in which these studies were conducted and plotted against the type of intervention or strategy implemented. Settings included primary care, emergency room/urgent care, outpatient general, outpatient pharmacy, outpatient surgery, dental, and dialysis. Strategies were grouped as: patient and/or clinician education only, audit and feedback, clinical decision support system, laboratory test, pharmacist review, delayed prescribing, pay for performance, public health campaigns, and multicomponent programs which included 2 or more specific strategies in addition to patient and/or clinician education. The highest concentration of studies occurred in the primary care setting with an audit and feedback intervention implemented.

### Characteristics of Primary Care Studies

Of 151 studies that included primary care sites, most were observational (k = 103) with only a fifth of these having concurrent comparators (k = 21); one third were RCTs (k = 48). Most studies were small to moderately sized (67% with ≤ 50 sites), while 20 included > 100 sites. Table 1 summarizes the characteristics of primary care studies categorized by specific antimicrobial stewardship strategy or multicomponent program. The most frequently implemented strategies were audit and feedback (k = 35) and patient/clinician education alone (k = 27). Multicomponent ASPs were also commonly examined (k = 32). Fewer studies evaluated CDSS (k = 16), new laboratory tests (k = 20), or the effects of public health campaigns (k = 13). The remaining strategies were rarely evaluated, and no study examined formulary restrictions as an individual strategy.

For studies evaluating multicomponent ASPs, the most common combination was audit and feedback with CDSS (k = 17); a few of these studies included additional strategies (eg, delayed prescribing, public health campaign, pay for performance; Figure 5). The remaining studies evaluated audit and feedback or CDSS combined with other strategies (k = 9), public health campaigns with pay for performance (k = 4), or laboratory test with either delayed prescribing or formulary restrictions (k = 2).

Table 1 Summary Characteristics of Primary Care Studies

Characteristic | Characteristic Grouping | Education Only^*^; (k = 27) | Audit & Feedback; (k = 35) | CDSS^†^; (k = 17) | Lab Tests; (k = 20) | Public Health; (k = 13) | Pharmacist Review; (k = 1) | Delayed Prescribing; (k = 5) | Pay for Performance; (k = 1) | Multi-Component^‡^; (k = 32)
Study design | RCT | 10 | 15 | 3 | 8 | – | – | 1 | – | 11
Study design | Observational concurrent comparator | 6 | 6 | – | 4 | 1 | – | – | – | 4
Study design | Observational single group | 11 | 14 | 14 | 8 | 12 | 1 | 4 | 1 | 17
# Prescribers | <50 | 7 | 6 | 3 | 9 | – | 1 | – | – | 2
# Prescribers | 50-200 | 6 | 8 | 3 | 4 | – | – | – | – | 4
# Prescribers | 201-500 | 2 | 1 | – | 4 | 2 | – | – | – | 4
# Prescribers | 501-1000 | 2 | 1 | 2 | – | 1 | – | – | – | 1
# Prescribers | >1000 | 2 | 6 | – | – | 3 | – | 1 | – | –
# Clinic sites | 1 | 5 | 3 | 8 | 1 | – | 1 | – | – | 3
# Clinic sites | 2-10 | 3 | 8 | 3 | 4 | 2 | – | 1 | – | 4
# Clinic sites | 11-50 | 3 | 4 | 2 | 3 | 1 | – | – | – | 8
# Clinic sites | 51-100 | 1 | 3 | 1 | 3 | 1 | – | 1 | – | 2
# Clinic sites | 101-200 | 2 | 1 | 2 | – | 1 | – | – | – | 3
# Clinic sites | >200 | – | 4 | – | 2 | 2 | – | – | 1 | 2
# Clinic sites | Very large national studies^§^ | – | – | – | – | – | – | 1 | – | –
Outcomes | Overall antimicrobial use | 23 | 30 | 16 | 14 | 7 | 1 | 3 | 1 | 28
Outcomes | Inappropriate prescribing | 5 | 16 | 11 | 4 | 2 | – | – | – | 15
Outcomes | Sustainability in prescribing^¶^ | 2 | 1 | – | 1 | – | – | – | – | –
Outcomes | Patient: treatment outcomes | 6 | 7 | 4 | 9 | 2 | – | – | – | 5
Outcomes | Patient: health care utilization^**^ | 1 | 8 | 5 | 5 | – | 1 | 1 | – | 4
Outcomes | Microbial resistance | – | 1 | 1 | – | 2 | – | – | 1 | 1
Outcomes | Staff satisfaction | 5 | 4 | 1 | 6 | 2 | – | – | – | 3
Outcomes | Implementation costs | 1 | 4 | – | 3 | – | – | 1 | – | –
Outcomes | Other barriers & facilitators | 1 | – | 1 | 7 | 1 | – | 1 | – | 4
Outcomes | Maintenance costs | – | 2 | – | 1 | – | – | – | – | –
Outcomes | Reach: patients, community | 1 | – | – | 1 | 2 | – | – | – | 1
Outcomes | Reach: prescribers, facilities | – | 2 | 2 | – | 2 | – | – | – | 2

Notes.

* Patient and/or clinician education.

† Tools embedded in electronic health records with computerized order entry.

‡ Programs included 2 or more specific strategies, in addition to patient and/or clinician education.

§ Includes 1 study in England and Wales with a patient population of 1.8 million.^11^

¶ Long-term effects on antimicrobial prescribing, at least 1 year after (and in a separate phase) from initial implementation.

** Includes hospital admissions, emergency room, and office visits.

Abbreviations. CDSS=clinical decision support system; RCT=randomized controlled trial.

Figure 5 Primary Care: Strategies Used in Multicomponent Antimicrobial Stewardship Programs

Abbreviations. A/F=audit and feedback; CDSS=clinical decision support system; Delay Rx=delayed prescribing; Pub Health=public health campaign; P4P=pay for performance.

A bar plot depicting the number of studies set in primary care investigating a multicomponent stewardship program by the components of each program. Each bar captures the number of studies that included a multicomponent program with a specific combination of components. The combinations include: audit and feedback with CDSS, audit and feedback with CDSS and delayed prescribing, audit and feedback with public health campaign and pay for performance, audit and feedback with lab tests, audit and feedback with lab tests and formulary restrictions, audit and feedback with public health campaign, audit and feedback with pay for performance, audit and feedback with delayed prescribing, CDSS with lab tests, laboratory tests with delayed prescribing, laboratory tests with formulary restrictions, and pubic health campaign with pay for performance.

The most commonly reported outcomes were overall antimicrobial use (k = 123, 82%), followed by inappropriate or appropriate antimicrobial prescribing (k = 53, 34%). Less than a quarter of studies assessed patient treatment outcomes (k = 33) or health care utilization (k = 25), and fewer examined staff satisfaction (k = 21). Rarely assessed outcomes included implementation barriers and facilitators (k = 15) or costs (k = 9), reach among patients (k = 5) or prescribers (k = 8), and sustainability (k = 4) or maintenance costs (k = 3). The general pattern of assessed outcomes remained the same across studies examining specific strategies, with the most frequently measured being antimicrobial prescribing (Table 1). For example, change in antimicrobial prescribing was reported by 86% of studies on audit and feedback (k = 30), and by 94% of studies evaluating CDSS (k = 16).

### Characteristics of Emergency Room/Urgent Care Studies

Of 95 primary studies conducted in the ER or urgent care setting, 87 were observational studies (14 with concurrent comparators), and the remaining 8 were RCTs. Nearly all studies included ≤ 10 sites (k = 67, 88%) and only 2 studies had > 100 sites. Table 2 summarizes characteristics for studies in ER/urgent care by specific antimicrobial strategy or multicomponent ASP. The most commonly used strategy was new laboratory tests (k = 21), followed by multicomponent ASPs (k = 18). Other individual strategies were patient/clinician education alone (k = 15), CDSS (k = 15), audit and feedback (k = 15), and pharmacist review (k = 11). No studies evaluated delayed prescribing, pay for performance measures, or public health campaigns.

For studies evaluating multicomponent ASPs in ER/urgent care settings, the most common combination was audit and feedback with CDSS (k = 9; Figure 6). The remaining studies examined audit and feedback or CDSS combined with other strategies (k = 7), or new laboratory tests with pharmacist review (k = 2).

Similar to studies in the primary care setting, change in overall antimicrobial prescribing was by far the most frequently reported outcome across all strategies and multicomponent ASPs (k = 76, 80%). Inappropriate or appropriate prescribing (k = 49, 51%), and patient health care utilization (k = 42, 47%) were also often assessed. A quarter of studies reported patient treatment outcomes (k = 27), and few examined staff satisfaction (k = 6), sustainability of prescribing changes (k = 3), or implementation costs (k = 3). Change in microbial resistance patterns, implementation barriers and facilitators, maintenance costs, and reach among prescribers were all rarely reported, with only a single study for each. No study assessed reach among patients or communities.

The general pattern of assessed outcomes was similar across studies examining specific strategies, with the most frequently measured outcome being overall antimicrobial prescribing. For example, in studies utilizing new laboratory tests, overall antimicrobial prescribing was reported by 86% of studies (k = 18), and among those evaluating CDSS, this was 73% (k = 11; %; Table 2). However, there were some differences, such as frequent reporting of inappropriate or appropriate prescribing by studies on audit and feedback (k = 13, 87%) and multicomponent programs (k = 11, 61%) but infrequent assessment by studies implementing new laboratory tests (k = 4, 19%). Patient health care utilization was more commonly assessed by studies in this latter group (k = 12, 57%).

Table 2 Summary Characteristics of Primary Studies Conducted in Emergency Room/Urgent Care

Characteristic | Characteristic Grouping | Education Only^*^; (k = 15) | Audit & Feedback; (k = 15) | CDSS^†^; (k = 15) | Lab Tests; (k = 21) | Pharmacist Review; (k = 11) | Multi-Component^‡^; (k = 18)
Study design | RCT | 1 | – | – | 7 | – | –
Study design | Observational concurrent comparator | 1 | 3 | 3 | 6 | – | 1
Study design | Observational single group | 13 | 12 | 12 | 8 | 11 | 17
# Prescribers | <50 | 3 | 1 | 2 | 1 | – | 1
# Prescribers | 50-200 | 2 | 3 | 1 | – | – | 2
# Prescribers | 201-500 | – | – | – | – | – | 1
# Prescribers | 501-1000 | – | – | 1 | – | – | –
# Prescribers | >1000 | – | – | 1 | – | – | –
# Clinic sites | 1 | 8 | 7 | 4 | 8 | 6 | 7
# Clinic sites | 2-10 | 4 | 5 | 4 | 8 | 2 | 4
# Clinic sites | 11-50 | – | 1 | 2 | 1 | – | 3
# Clinic sites | 101-200 | – | – | 2 | – | – | –
Outcomes | Overall antimicrobial use | 10 | 12 | 11 | 18 | 10 | 15
Outcomes | Inappropriate prescribing | 7 | 12 | 8 | 4 | 6 | 11
Outcomes | Sustainability in prescribing^¶^ | 1 | – | 1 | – | – | 1
Outcomes | Patient: treatment outcomes | 4 | 6 | 5 | 7 | 2 | 2
Outcomes | Patient: health care utilization^§^ | 4 | 6 | 5 | 12 | 6 | 9
Outcomes | Microbial resistance | – | 1 | – | – | – | –
Outcomes | Staff satisfaction | 2 | – | 2 | 2 | – | –
Outcomes | Implementation costs | – | 1 | 1 | 1 | – | –
Outcomes | Other barriers & facilitators | – | – | 1 | – | – | –
Outcomes | Maintenance costs | – | 1 | – | – | – | –
Outcomes | Reach: prescribers, facilities | – | – | 1 | – | – | –

Notes.

* Patient and/or clinician education.

† Tools embedded in electronic health records with computerized order entry.

‡ Programs included 2 or more specific strategies, in addition to patient and/or clinician education.

§ Includes hospital admissions, emergency room, and office visits.

¶ Long-term effects on antimicrobial prescribing, at least 1 year after (and in a separate phase) from initial implementation.

Abbreviations. CDSS=clinical decision support system; RCT=randomized controlled trial.

Figure 6 Emergency Room/Urgent Care: Strategies Used in Multicomponent Antimicrobial Stewardship Programs

Abbreviations. A/F=audit and feedback; CDSS=clinical decision support system; Pub Health=public health campaign; P4P=pay for performance.

A bar plot of studies set in the emergency room and urgent care with multicomponent stewardship strategies depicting the number of studies in each combination of strategies. The combinations include: audit and feedback with CDSS, audit and feedback with public health campaign, audit and feedback with pharmacist review, audit and feedback with lab tests and pay for performance, CDSS with pharmacist review, CDSS with formulary restrictions, and laboratory tests with pharmacist review.

### Characteristics of Studies Conducted in Other Outpatient Settings

The remaining 58 eligible primary studies were conducted in a variety of settings, including general non-specific outpatient (or multiple clinic types; k = 36), outpatient pharmacy (k = 11), dental clinic (k = 6), outpatient surgery (k = 4), and dialysis facilities (k = 1). Of these studies, 54 were observational studies, 7 of which had concurrent comparators, and 4 were RCTs. Study sizes varied substantially, with some including only 1 clinic site (k = 11) and a few that were national in scope, reporting data for millions of unique patients (k = 3). Table 3 summarizes the characteristics of these studies, categorized by antimicrobial stewardship strategy or program. These studies most often evaluated patient/clinician education alone (k = 13), CDSS (k = 11), multicomponent ASPs (k = 10), or public health campaigns (k = 9). Fewer studies examined specifically audit and feedback (k = 4), new laboratory tests (k = 4), pharmacist review (k = 3), and delayed prescribing (k = 3). Only 1 study evaluated pay for performance. Most multicomponent ASPs included audit and feedback combined with 1 or more additional strategies (k = 7).

Change in antimicrobial prescribing was the most frequently reported outcome (k = 48, 83%), while fewer studies addressed inappropriate or appropriate prescribing (k = 18, 31%), patient treatment outcomes (k = 15, 26%), or health care utilization (k = 13, 22%). All other outcomes were rarely assessed, and no study examined sustainability of prescribing changes or reach among patients. These patterns were similar across studies on specific antimicrobial stewardship strategies or programs, with a few differences, such as more studies on CDSS reported inappropriate prescribing (k = 6, 55%; Table 3).

Table 3 Summary Characteristics of Studies Conducted in Other Outpatient Settings

Characteristic | Characteristic Grouping | Education Only^*^; (k = 13) | Audit & Feedback; (k = 4) | CDSS^†^; (k = 11) | Lab Tests; (k = 4) | Public Health; (k = 9) | Pharmacist Review; (k = 3) | Delayed Prescribing; (k = 3) | Pay for Performance; (k = 1) | Multi-Component^‡^; (k = 10)
Setting | Outpatient, general | 6 | 1 | 10 | 2 | 6 | 1 | 3 | 1 | 6
Setting | Outpatient surgery | 2 | – | 1 | – | – | 1 | – | – | –
Setting | Outpatient pharmacy | 2 | – | – | 2 | 3 | 1 | – | – | 3
Setting | Dialysis | – | 1 | – | – | – | – | – | – | –
Setting | Dental | 3 | 2 | – | – | – | – | – | – | 1
Study design | RCT | 1 | – | – | – | – | – | 2 | – | 1
Study design | Observational concurrent comparator | 3 | – | 1 | 1 | 2 | – | – | – | –
Study design | Observational single group | 9 | 4 | 10 | 3 | 7 | 3 | 1 | 1 | 9
# Prescribers | <50 | 1 | 3 | – | 1 | – | – | – | – | –
# Prescribers | 50-200 | 1 | – | – | – | – | – | 1 | – | 1
# Prescribers | >1000 | – | – | 1 | – | – | – | – | – | –
# Clinic sites | 1 | 4 | – | 3 | – | 1 | 1 | – | – | 2
# Clinic sites | 2-10 | 1 | 1 | – | – | – | – | – | – | 1
# Clinic sites | 11-50 | – | – | 1 | – | – | – | 2 | – | –
# Clinic sites | 51-100 | – | – | – | 1 | – | – | – | – | 1
# Clinic sites | >200 | 2 | – | – | – | – | 1 | – | – | –
# Clinic sites | Very large national studies ^§^ | – | – | – | – | – | 1 | 1 | 1 | –
Outcomes ^¶^ | Overall antimicrobial use | 10 | 3 | 9 | 3 | 9 | 2 | 2 | 1 | 9
Outcomes ^¶^ | Inappropriate prescribing | 2 | 3 | 6 | 1 | 3 | – | – | – | 3
Outcomes ^¶^ | Patient: treatment outcomes | 4 | 1 | 2 | 1 | 2 | 1 | 1 | – | 3
Outcomes ^¶^ | Patient: health care utilization^**^ | 3 | 1 | 4 | 2 | – | – | 1 | – | 2
Outcomes ^¶^ | Microbial resistance | 1 | – | 1 | – | – | 1 | – | – | 1
Outcomes ^¶^ | Staff satisfaction | 1 | – | – | 1 | – | 1 | 1 | – | 2
Outcomes ^¶^ | Implementation costs | – | – | 1 | 1 | 1 | – | 1 | – | 3
Outcomes ^¶^ | Other barriers & facilitators | – | 1 | – | 1 | – | 1 | 1 | – | 1
Outcomes ^¶^ | Maintenance costs | – | – | – | – | 1 | – | – | – | 1
Outcomes ^¶^ | Reach: prescribers, facilities | – | – | – | – | – | 1 | – | – | –

Notes.

* Patient and/or clinician education.

† Tools embedded in electronic health records with computerized order entry.

‡ Programs included 2 or more specific strategies, in addition to patient and/or clinician education.

§ Two studies in Japan included a population of 2.9 million patients^12^ and 13.5 million patients.^13^ One study in England and Wales included a population of 1.8 million patients.^11^

¶ No studies reported sustainability in effects on prescribing or reach for patients and communities.

** Includes hospital admissions, emergency room, and office visits.

Abbreviations. CDSS=clinical decision support system; RCT=randomized controlled trial.

### Characteristics of Systematic Reviews on Antimicrobial Stewardship Programs or Strategies

The 37 eligible systematic reviews included 10–59 primary studies and addressed evidence in various outpatient settings, including primary care (k = 17), ER/urgent care (k = 5), general outpatient (k = 5), outpatient pharmacy (k = 2), and dental clinics (k = 1). Seven reviews included studies conducted across a range of outpatient settings. Reviews included studies focused on a variety of stewardship strategies, with education only, audit and feedback, CDSS, and new laboratory tests being the most common (Figure 7). For outcomes of interest, antimicrobial prescribing was the most common (k = 34), followed by patient treatment outcomes (k = 20) and health care utilization (k = 12). Ten reviews examined inappropriate or appropriate prescribing, and few addressed implementation costs (k = 4) or other barriers and facilitators (k = 3), staff satisfaction (k = 2), changes in microbial resistance (k = 1), or maintenance costs (k = 1).

Figure 7 Eligible Systematic Reviews: Antimicrobial Stewardship Strategies

Abbreviations. CDSS=clinical decision support system; P4P=pay for performance.

A bar plot of included systematic reviews summarizing the antimicrobial stewardship strategy of focus for each review. The strategies include: education only, audit and feedback, CDSS, new laboratory tests, public health campaign, pharmacist review, delayed prescribing, pay for performance, and formulary restrictions.

## PRIORITIZED STUDIES EVALUATING AUDIT AND FEEDBACK, CDSS, AND MULTICOMPONENT STEWARDSHIP PROGRAMS IN PRIMARY CARE AND EMERGENCY ROOM SETTINGS

We prioritized 45 primary studies for more detailed data abstraction and synthesis, including 29 RCTs and 16 observational studies with concurrent comparators. The majority of studies had moderate/some concerns for RoB (k = 25), while 12 had low RoB and 8 had high RoB. Most prioritized studies were conducted in primary care (k = 37) and fewer were conducted in ER (k = 6). Two studies included multiple clinical settings (primary care plus either ER or outpatient pharmacy). No eligible studies in urgent care or general outpatient settings met other prioritization criteria (for ASP or strategy, and study design; see Methods).

Table 4 summarizes the characteristics of prioritized studies by the ASP or strategy being evaluated. Detailed study characteristics and RoB ratings for all prioritized studies are provided in the Supplementary Materials. Half of the studies focused on antimicrobial prescribing for respiratory conditions (k = 23), and a third addressed general antibiotic prescribing or included multiple conditions of interest (k = 15). The remaining studies focused on urinary tract infections (k = 5) or cellulitis (k = 2). Studies were mainly conducted in North America (k = 23) and Europe (k = 12). A third of studies occurred in large regional or national health care systems (European, Canadian, and VA) (k = 16), while the remaining occurred in large private integrated health care systems (k = 13) or individual community clinics (k = 8).

Table 4 Summary Characteristics of Prioritized Studies (k = 45)

Characteristics | Characteristic Groupings | Audit & Feedback^*^; (k = 25) | CDSS^†^; (k = 6) | Multicomponent: Audit & Feedback and CDSS^‡^; (k = 10) | Other Multicomponent Programs^§^; (k = 4)
Study design | RCT | 17 | 3 | 7 | 2
Study design | Observational | 8 | 3 | 3 | 2
Risk of bias | Low | 9 | 1 | 2 | –
Risk of bias | Moderate/some concerns | 14 | 4 | 5 | 2
Risk of bias | High | 2 | 1 | 3 | 2
Outpatient setting ^¶^ | Primary care | 23 | 3 | 9 | 4
Outpatient setting ^¶^ | Emergency room | 3 | 3 | 1 | –
Clinical focus | General/multiple conditions | 12 | – | 1 | 2
Clinical focus | Respiratory infections | 9 | 5 | 7 | 2
Clinical focus | Urinary tract infection | 4 | – | 1 | –
Clinical focus | Cellulitis | – | 1 | 1 | –
National or large regional health system | United States^**^ | 2 | – | – | –
National or large regional health system | Canada | 4 | – | – | –
National or large regional health system | Europe | 7 | 1 | 2 | 2
National or large regional health system | Australia | – | – | – | 1
Private health care setting | Large integrated system^††^ | 4 | 5 | 4 | 1
Private health care setting | Individual community clinics | 9 | – | 4 | –
Location | United States | 8 | 5 | 5 | –
Location | Canada | 4 | – | – | 1
Location | United Kingdom and Ireland | 6 | 1 | 3 | 1
Location | Continental Europe | 6 | – | 2 | 1
Location | Australia | – | – | – | 1
Location | Multiple countries | 1 | – | – | –
Outcomes | Overall antimicrobial use | 21 | 5 | 8 | 4
Outcomes | Inappropriate prescribing | 13 | 4 | 8 | 1
Outcomes | Sustainability | 1 | – | – | –
Outcomes | Patient: treatment outcomes | 5 | 2 | 1 | –
Outcomes | Patient: health care utilization^‡‡^ | 5 | 3 | 1 | –
Outcomes | Microbial resistance | – | – | – | –
Outcomes | Staff satisfaction | 3 | – | 2 | –
Outcomes | Implementation costs | 2 | – | – | –
Outcomes | Other barriers & facilitators | 1 | – | 1 | 1
Outcomes | Reach: patients, community | – | – | – | –
Outcomes | Reach: prescribers, facilities | 2 | 3 | – | –

Notes.

* Studies all included clinician and/or patient education; 2 studies also included public health campaign in both arms.^14,15^

† Tools embedded in the electronic health record with computerized order entry, also may have included clinician and/or patient education.

‡ Programs included 2 or more specific strategies in addition to clinician and/or patient education. All studies evaluated at least 1 arm that had combined audit and feedback and CDSS, and 5 studies included other additional strategies (delayed prescribing [k = 3], laboratory test [k = 1], and pay for performance and patient medication assistance [k = 1]).

§ Programs included 2 or more specific strategies, in addition to clinician and/or patient education. Two studies examined audit and feedback with delayed prescribing (McIsaac, 2021^16^; Goodchild, 2018^17^). The third study evaluated combination of delayed prescribing with laboratory tests compared with usual care (Tonkin-Crine, 2023^18^), and another used audit and feedback with laboratory tests, also compared with usual care (Llor, 3018^19^).

¶ These categories are not mutually exclusive.

** Both studies conducted in Veterans Health Administration.

†† Private integrated health systems with variable numbers of associated outpatient clinics and/or emergency rooms.

‡‡ Includes hospital admissions, emergency room, and office visits.

Abbreviations. CDSS=clinical decision support system; RCT=randomized controlled trial.

Twenty-five prioritized studies evaluated audit and feedback, all with patient and/or clinician education (k = 23) or education and ongoing public health campaign (k = 2).^14,15,20–42^ Table 5 provides summary characteristics of these studies, including additional information on frequency and format of audit and feedback. Eight were observational studies with concurrent comparators^21,22,24,30,31,36,38,40^ and the remaining 15 were RCTs.^20,23,25–29,32–35,37,39,41,42^ Nine studies were low RoB,^23,25,26,32–34,37,39,41^ 14 were moderate/some concerns,^14,15,20–22,24,27–31,35,36,38^ and 2 had high RoB.^40,42^ Study duration ranged 6–36 months, with the majority of studies (k = 18) being ≥ 12 months.^14,21–34,37,38,41^ The frequency of audit and feedback varied across the included studies, with 14 studies^21,22,24,25,27–30,32,34,37–39,42^ reporting at least 2 rounds of audit and feedback. Reference groups for feedback on prescribing included clinic peers, regional peers, national peers, the top 20% performers, and national and guideline benchmarks. All studies compared audit and feedback with usual care. Three of the included studies^23,26,36^ did not report the comparator group, 14 studies^20,21,24,25,27,29–33,35,37–39^ used a peer or clinic comparison group when providing audit and feedback, and the remaining 6 studies^22,29,34,35,40,42^ used a national or guideline benchmark. Methods of communicating the audit and feedback included a letter, email, and online dashboard. The majority of studies (k = 22) used a letter or email to communicate with intervention participants, and a single study^30^ used an online dashboard that participants could access at any time over the study time period. The majority of studies assessed change in overall prescribing (k = 22)^14,20–32,34,35,37–42^ or a change in inappropriate or appropriate prescribing (k = 12).^20,22,24,27,28,30,31,33,36,38,39,42^ Fewer studies reported patient treatment outcomes (k = 4)^28,31,38,41^ and health care utilization (k = 5).^28,31,32,34,38^

Table 5 Summary Characteristics of Audit and Feedback Studies (k = 25)

General or Multiple Conditions Addressed

Audit & Feedback Frequency | Author, Year;; Study Design;; Risk of Bias | Feedback Format & Content | Study Duration^*^
Once | Gold, 2022^35^; RCT; Some concerns | Letters; Practice level comparisons, all England | 6 mo
Once | Ratajczak, 2019^40^; Observational; High | Letters; Compared nationally | 6 mo
Once | Schwartz, 2021^23^; RCT; Low | Letters; Content NR | 24 mo
Once | Schwartz, 2024^20^; RCT; Some concerns | Letters; Other clinicians with similar case mix | 6 mo
Once | Feldmeier, 2023^14^; RCT; Some concerns | Letters; Other clinicians in same practice | 19 mo
Once | McNulty, 2018^15^; RCT; Some concerns | Letters; Compared nationally | 12 mo
Monthly | Dutcher, 2021^42^; RCT; High | Letters; Compared with clinic guidelines | 12 mo
Every 3-6 months | Aghlmandi, 2023^32^; RCT; Low | Letters; Peer physicians | 24 mo
Every 3-6 months | Hemkens, 2017^25^; RCT; Low | Letters; Adjusted average in peer physicians | 24 mo
Every 3-6 months | Hurlimann, 2015^27^; RCT; Some concerns | Letters; Other clinicians in the intervention | 24 mo
Every 3-6 months | Marwick, 2022^34^; RCT; Low | Emails; Health board and national benchmarks | 24 mo
Every 3-6 months | Soucy, 2024^21^; Observational; Moderate | Emails; Other intervention providers | 36 mo
Every 5 weeks | Curtis, 2021^37^; RCT; Low | Fax, email, and letter; Practice level comparison to other practices | 7 mo

Focus on Respiratory Infections

Audit & Feedback Frequency | Author, Year;; Study Design;; Risk of Bias | Feedback Format & Content | Study Duration^*^
Once | Gulliford, 2019^41^; RCT; Low | Electronically delivered; Previous 12 months of prescribing | 12 mo
Once | Livorsi, 2021^31^; Observational; Moderate | In-person meetings; Other local peers | 12 mo
Once | Singer, 2022^33^; RCT; Low | Format NR; Peer and regional physicians | 24 mo
Every 6 months | Jones, 2021^30^; Observational; Moderate | Email; Other clinicians in the study | 21 mo
Every 6 months | van der Velden, 2016^26^,^†^; RCT; Low | In person during meetings; Content NR | 24 mo
Every 2–4 weeks | Du Yan, 2021^39^; RCT; Low | Online dashboard; Compared with the practice | 7 mo
Every 2–4 weeks | Madaras-Kelly, 2021^38^; Observational; Moderate | In person or by email; Clinic setting and top 20% performers | 12 mo
Every 2–4 weeks | Milani, 2019^24^; Observational; Moderate | Email; Other clinicians within the test region | 21 mo
Every 2–4 weeks | Guo, 2020^22^; Observational; Moderate | In person; No peer comparison | 15 mo

Focus on Urinary Tract Infections

Audit & Feedback Frequency | Author, Year;; Study Design;; Risk of Bias | Feedback Format & Content | Study Duration^*^
Once | Grigoryan, 2021^36^; Observational; Moderate | In person and by telephone; Content NR | 11 mo
Every 3-6 months | Carney, 2023^29^; RCT; Some concerns | Letters; British Columbia clinicians | 12 mo
Every 3-6 months | Schmiemann, 2023^28^; RCT; Some concerns | By telephone; Compared with regional clinicians | 15 mo

Notes.

* Total study duration includes implementation time and total follow-up time.

† Comparator group received audit and feedback focused on prescribing of proton-pump inhibitor.

Abbreviations. mo=month; NR=not reported; RCT=randomized controlled trial.

Six studies^43–48^ compared CDSS with usual care; 3 were RCTs^44,46,48^ and 3 were observational.^43,45,47^ CDSS characteristics and other study information are summarized in Table 6. Three studies had some concerns/moderate RoB,^45–47^ 1 had low RoB,^43^ and 1 had high RoB.^48^ Most studies^43,46,48^ had total duration ≥ 12 months.^43–46,48^ Half of the studies occurred in primary care settings^44,46,48^ and half in ER.^43,45,47^ Notably, all studies were conducted either in a national health system in Europe^46^ or in private integrated health care systems within the US.^43,45,47,48^ All studies employed CDSS that were activated by certain diagnoses, orders, or other information in the EHR. All presented information on diagnosis and recommendations for antimicrobial prescribing, with the majority leading to specific order sets that supported next steps in care.^43–45,48^ ^46,48^ Five studies^43–46,48^ addressed respiratory infections and 1 study^47^ focused on cellulitis.

Table 6 Summary Characteristics of Studies Evaluating Clinical Decision Support System/Tools (k = 6)

Author, Year;; Study Design;; Risk of Bias;; Study Duration | Characteristics of Clinical Decision Support System/Tools^*^
Dean, 2015^45^; Observational (2 groups); Moderate; 18 mo | Tool drew upon various data in EHR (including previous encounters and data for same patient) and activated when calculated probability of pneumonia ≥ 40%; Presented further prediction of clinical severity (using established calculators) with potential to correct and add more information, makes diagnostic and management recommendations (including antibiotics)
Dean, 2022^43^; Observational (6 clusters in stepped wedge design)^†^; Low; 16 mo | Same clinical decision support tools as described in Dean, 2015^45^ (deployed at additional emergency room sites within the same health system)
Dezman, 2023^47^; Observational (2 groups); Moderate; 6 mo | Activated by diagnosis codes for cellulitis; Prompted entry of additional clinical information, then determines list of most likely diagnoses and list of most dangerous diagnoses
Gulliford, 2014^46^; RCT (2 arms); Some concerns; 12 mo | Activated by diagnosis codes for respiratory conditions or symptoms (eg, bronchitis, cough); Presented antibiotic prescribing guidelines and research data; Provided printable patient education materials (1 page)
Mann, 2020^48^; RCT (2 arms); High; 33 mo | Activated by visit reason or diagnosis codes +/− antibiotics prescription for acute respiratory infection; Integrated clinical prediction tools for pneumonia and streptococcal pharyngitis, led to different recommended diagnostic and treatment (including antibiotics) order sets
McGinn, 2013^44^; RCT (2 arms); Some concerns; 12 mo | Activated by visit reason, diagnosis codes, and/or test orders related to pharyngitis or pneumonia; Requested clinician to complete prediction tools for pneumonia and streptococcal pharyngitis, led to different recommended diagnostic and treatment (including antibiotics) order sets

Notes.

* Included alerts, tools, and decision aids integrated into medical record systems with computerized order entry.

† Sixteen emergency room sites grouped in 6 clusters with different staggered timing for implementation.

Abbreviations. EHR=electronic health record; mo=months; RCT=randomized controlled trial.

Of 14 studies evaluating multicomponent ASPs, 10 evaluated audit and feedback combined with CDSS in at least 1 arm, often with other additional strategies. Characteristics of these 10 studies are summarized in Table 7. Five studies^49–54^ focused primarily on comparing combined audit and feedback and CDSS with usual care or clinician education, with 2 of these also including different versions of CDSS in separate arms.^52,53^ Three other studies included delayed prescribing,^55–57^ and 1 study examined the additional effects of C-reactive protein (CRP) testing versus CDSS in addition to audit and feedback and clinician education.^58^ The tenth study included audit and feedback, clinician education, pay for performance, and public health campaign in all 3 arms, and compared the impact of additionally providing patient medications versus CDSS in separate arms.^59^ Audit and feedback frequency ranged from once^54–56,59^ to 3 times during the study,^58^ or quarterly^50^ to monthly.^49,52,53,57^ CDSS components also varied substantially, with most providing diagnostic and treatment recommendations information (Table 7). Most studies were RCTs (k = 7),^52–57,59^ and 3 were comparative observational studies.^49,58,60^ All studies were conducted the US or Europe and occurred mainly in large private integrated health care systems (k = 4),^49,52–54^ or in individual community clinics (k = 4).^50,55,57,58^ Two studies were conducted in large regional or national health care systems.^56,59^ Study duration ranged from 6–21 months, and included 54–579 prescribers, or 1–196 clinic sites. Antimicrobial stewardship programs most often focused on respiratory infections (k = 7),^50,52–56,58^ and fewer addressed general prescribing or multiple conditions (k = 1),^59^ urinary tract infections (k = 1),^57^ or cellulitis (k = 1).^49^

Of the remaining 4 studies evaluating multicomponent ASPs, 1^19^ compared a combination of audit and feedback, introduction of CRP testing, and patient/clinician education versus usual care. This was an observational study conducted in 8 regions of Spain and included 210 general practitioners. Audit and feedback occurred twice during the program. The second study^18^ also involved CRP testing and patient/clinician education but added a focus on delayed prescribing. This observational study included 9 English general practices which participated in the ASP and 45 control practices. The third study, an RCT, was conducted in 6 (3 control and 3 intervention arms) primary care clinics in Toronto, Canada and compared clinical decision aids paired with a clinical decision support tool and audit and feedback.^16^ The fourth study, another RCT, was conducted in Australia and randomized clinics to 1 of 4 interventions or a control arm.^17^ The interventions included education alone, 2 different versions of audit and feedback, and audit and feedback with delayed prescribing.

Table 7 Summary Characteristics of Studies Evaluating Multicomponent Antimicrobial Stewardship Programs with Combined Audit and Feedback and CDSS (k = 10)

Author, Year;; Study Design;; Risk of Bias;; Study Duration | Characteristics of Clinical Decision Support System/Tools^*^ | Audit and Feedback Frequency, Format | Additional Strategies^†^
Colliers, 2023^58^; Observational (4 groups); High; 18 mo | Activated by diagnosis codes for otitis, tonsillitis or bronchitis; Presented advice on antibiotic prescribing | 3 times during study; Content and format NR | CRP testing (1 group only)
Gonzales, 2013^54^; RCT (3 arms); Some concerns; 6 mo | Activated by “cough as chief symptom”; Requested clinician to complete prediction tool, led to different recommended diagnostic and treatment (including antibiotics) ordersets | Once; In person meeting, comparisons NR | None
Gjelstad, 2013^51^; Hoye, 2013^55^; RCT (3 arms); High; 12 mo | Activated by order for “antibiotic typically used for respiratory tract infections”; Requested clinician to document if this was delayed prescription (and how many days for delay) | Twice; In person meeting and mailed reports, compared to other clinicians in the study | Delayed prescribing emphasized in clinician education (2 arms)
Mainous, 2013^50^; Observational (2 groups); Moderate; 15 mo | Structured template that could be selected by clinician (activating criteria NR); Requested clinician to complete key information, led to different diagnosis and treatment recommendations (including antibiotics) for respiratory infections | Quarterly; In person meeting, comparisons NR | None
May, 2021^49^; Observational (2 groups); High; 10 mo | Treatment algorithm and ordersets for skin and soft tissue infections (activating criteria and orderset content NR) | Monthly; Emailed reports, compared to other clinicians in the study | None
Meeker, 2016^52^; RCT (8 arms); Some concerns; 18 mo | 2 different decision support tools (implemented in every possible combination—individually or both, +/− audit and feedback); - Activated by antibiotic prescription for respiratory infection, presented treatment recommendations, required clinician justification for antibiotics; - Activated by diagnosis for respiratory infection, presented treatment recommendations (including antibiotics) and patient education materials | Monthly; Emailed reports, compared to lowest decile (for antibiotic prescribing) of clinicians within clinic | None
Persell, 2016^53^; RCT (8 arms); Low; 12 mo | Same clinicial decision support tool and study design, was pilot study for Meeker, 201652 | Monthly; Emailed reports, compared to lowest decile (for antibiotic prescribing) of clinicians within clinic | None
Poss-Doering, 2021^59^; RCT (3 arms); Some concerns; 21 mo | Activated by diagnosis codes or antibiotic prescriptions for range of respiratory conditions, cystitis, etc.; Presented antibiotic recommendations | 4 times; In person meetings, comparisons NR | Pay for performance, social media campaign (all arms); Medication assistance (1 arm)
Vellinga, 2016^57^; RCT (3 arms); Low; 7 mo | Activated by diagnosis codes for urinary tract infection; Presented antibiotic recommendations (2 arms), one arm also included delayed antibiotic prescribing | At least once; In person meeting and then monthly data available electronically, compared with other practices in study | Delayed prescribing (1 arm)
Vervloet, 2016^56^; RCT (2 arms); Some concerns; 12 mo | Activated by diagnosis of respiratory conditions; Recommended no antibiotics, then suggests delayed antibiotic prescription (if clinician rejects initial recommendation), then normal antibiotic prescription (if clinician rejects delayed prescription) | Once; Content and format NR | Delayed prescribing (1 arm)

Notes.

* Included alerts, tools, and decision-aids integrated into medical record systems with computerized order entry.

† Beyond clinical decision support systems/tools, audit and feedback, or patient and/or clinician education.

Abbreviations. mo=months; NR=not reported; RCT=randomized controlled trial.

Below, we present the findings for outcome categories, beginning with antimicrobial prescribing, grouped by various comparisons (eg, audit and feedback vs usual care). No prioritized study reported on sustainability, microbial resistance patterns, or reach among patients and communities. We completed meta-analyses for findings in prioritized studies if there were ≥ 3 studies that evaluated an outcome in a similar manner and time point, and the reported effect measure was conducive to the analysis. Detailed findings for all eligible outcomes reported by prioritized studies are found in the Supplementary Materials.

### Antimicrobial Prescribing

#### Audit and Feedback versus Usual Care

Twenty studies compared the effect of audit and feedback versus usual care on overall antimicrobial prescribing.^14,15,20–23,25–32,34,35,37,38,40,41^ We included data from 8 studies^14,15,17,28,30,31,38,41^ in a quantitative meta-analysis; these studies all assessed changes in overall antimicrobial prescribing ≥ 12 months after implementation, were general in scope or focused on respiratory conditions, and reported the effect measures appropriate for meta-analysis. The pooled estimate was RR = 0.89, 95% CI [0.77, 1.03], indicating no differences comparing audit and feedback versus usual care at the latest follow-up time point; there was high heterogeneity (Figure 8). Studies not contributing data to the meta-analysis included 2 studies that focused solely on decreasing ciprofloxacin prescribing for urinary tract infections,^22,29^ and 1 study that sought to increase penicillin prescribing for respiratory infections and sulfamethoxazole/trimethoprim for urinary tract infections.^27^ There were also 11 studies that did not report data amenable for analysis (eg, only mean or median prescribing rates across practices, model estimated rates, or between-group differences in rates or change in rates pre-post implementation).^20,21,23,25,26,32,34,35,37,40,42^

Figure 8 Audit and Feedback versus Usual Care: Overall Antimicrobial Prescribing

Notes. *Trial authors reported counts in patient years.

**Review team calculated total number of visits.

***Review team included arms with peer comparison versus control and peer comparison with graph versus control.

A forest plot of changes in overall antimicrobial prescribing. Included studies investigated implementation of an audit and feedback program and captured the change in overall prescribing at least 12 months after implementation. When pooled, there were no differences comparing audit and feedback versus usual care at the latest follow-up timepoint.

Fourteen studies^20,22,24,26–28,30,31,33,36,38,39,52,53^ evaluated inappropriate and/or appropriate prescribing for audit and feedback versus usual care. We included 5 studies^30,31,38,52,53^ in a meta-analysis on the impact of audit and feedback on inappropriate prescribing for respiratory infections; outcomes were examined at 12–21 months and defined as proportion of patient visits with antibiotics prescribed out of all visits that were categorized as inappropriate or unnecessary. Two of these studies were multi-arm evaluations of multicomponent ASPs but included audit and feedback versus usual care in 2 arms (out of 8 arms).^52,53^ There were no differences between groups in rates of inappropriate prescribing (pooled RR = 0.80, 95% CI [0.41, 1.57]) and there was high heterogeneity (Figure 9). Among studies not included in the meta-analysis, 3 focused on improving prescribing for urinary tract infections but defined inappropriate versus appropriate differently (2 solely by choice of antibiotic and 1 by choice and duration of antibiotics).^22,28,36^ Another study sought to increase specific antibiotics for urinary tract and respiratory infections and to decrease fluoroquinolones for chronic lung disease.^27^ The remaining 5 studies not included in the meta-analysis all reported outcomes that were variably assessed and not amenable to pooling (eg, mean prescribing rates across practices, only change in prescribing rates, proportion of prescribers who reduced prescribing by 1%).^20,24,26,33,39^

Figure 9 Audit and Feedback versus Usual Care: Inappropriate Antimicrobial Prescribing

A forest plot of change in inappropriate and/or appropriate prescribing. Included studies investigated implementation of an audit and feedback program and captured the change in inappropriate prescribing between at 12-21 months after implementation. When pooled, there were no differences comparing audit and feedback versus usual care in rates of inappropriate prescribing.

#### Clinical Decision Support System versus Usual Care

Five studies^43,46–48,51^ evaluated overall antimicrobial prescribing for CDSS versus usual care. Three studies were RCTs with duration of 12–33 months^44,46,48^ and 1 was observational with 16 months of follow-up.^43^ A meta-analysis was not done, as studies varied substantially in focus of CDSS and definition of outcomes. Four studies^43,44,46,48^ focused on antimicrobial prescribing for respiratory tract infections, with 1 of these solely addressing antibiotic prescribing for pneumonia.^43^ In contrast, Dezman 2022^47^ conducted a case-control study to evaluate a CDSS tool employing a photo-based differential to help clinicians come to a diagnosis for cellulitis; it showed lower overall prescribing for patient visits where the tool had been activated (69% vs 78% control, p < 0.001). The 4 studies examining CDSS for respiratory conditions showed inconsistent results. Mann, 2020 found no difference in overall antibiotic prescription rates between CDSS and control groups (35% vs 36%, p = 0.78),^48^ while McGinn, 2013^44^ showed lower overall antibiotics in the CDSS arm (29% vs 38% for control, p = 0.008); both of these studies evaluated a similar CDSS for pneumonia and streptococcal pharyngitis. Gulliford, 2014^46^ assessed mean antibiotic prescription rates across practices and found similar results between groups (mean 108 in CDSS practices vs 114 in control practices, both per 1,000 patient years, p-value NR). The fourth study used a stepped-wedge design to evaluate time to administration of first antibiotic and use of broad-spectrum coverage for resistant organisms to treat pneumonia, finding a small reduction in use of vancomycin (for methicillin-resistant Staphylococcus aureus) after implementation of the CDSS tool (10% vs 13% before, p < 0.001).^43^

Five studies^43,45,48,52,53^ evaluated the effect of implementing a CDSS tool on inappropriate prescribing, compared with usual care. Three studies^48,52,53^ primarily addressed reduction of inappropriate prescribing for respiratory infections and were included in the meta-analysis; outcomes were examined at 12–33 months and defined as noted above for audit and feedback comparisons (Figure 10). Two of these studies evaluated multicomponent ASPs and also included arms with only CDSS versus usual care.^52,53^ There were no differences between groups in rates of inappropriate prescribing (pooled RR = 1.08, 95% CI [0.59, 1.97]) and there was substantial heterogeneity (Figure 10). The 2 studies not included in the meta-analysis implemented a CDSS focused on increasing appropriate antimicrobial selection for pneumonia in the ER (eg, shorter time to antibiotic administration and coverage of atypical organisms).^43,45^

Figure 10 CDSS versus Usual Care: Inappropriate Antimicrobial Prescribing

A forest plot of inappropriate prescribing. Included studies investigated implementation of a CDSS program and examined inappropriate prescribing at between 12-33 months of follow up. When pooled, there were no differences comparing CDSS versus usual care in rates of inappropriate prescribing.

#### Multicomponent Antimicrobial Stewardship Programs: Audit and Feedback and CDSS versus Usual Care

Among studies using multicomponent programs, 6 evaluated the effects of combined audit and feedback and CDSS versus usual care on antimicrobial prescribing outcomes. Three RCTs and 1 observational study focused on respiratory infections (k = 4),^52,53,56,58^ an RCT addressed urinary tract infections,^57^ and the final RCT tackled both groups of infections.^16^ Four studies assessed overall antimicrobial prescribing over 6–12 months, but we were unable to conduct meta-analysis due to lack of appropriate data reported by 1 study (it did not provide the absolute number of prescriptions per visit or patient at each)^56^ and the focus being substantially different in the single study on urinary tract infections.^57^ This latter study sought to encourage selection of nitrofurantoin as first-line therapy and demonstrated an unintended increase in overall antibiotic prescribing.^57^ The 3 other studies all found that the ASP arms had higher overall prescribing rates after or during the study period (eg, 49% versus 43% usual care group),^16^ but in each study the usual care group had lower baseline prescribing rates (eg, 38% for audit and feedback and CDSS vs 34% for usual care).^16^ Two of these reported greater reductions in overall prescribing comparing the change over time between groups,^56,58^ and 1 indicated that the intervention group had lower odds of antibiotic prescriptions after adjustment for case mix and patient demographics (OR = 0.78, 95% CI [0.64, 0.96]).^16^

Four studies reported on inappropriate or appropriate antimicrobial prescribing, including the single RCT focused on urinary tract infections,^57^ and 3 RCTs that addressed respiratory infections.^52–54^ We were unable to conduct meta-analysis due to differences in the clinical focus and the duration of follow-up (2 studies with 6 months and 2 with 12–18 months). Two RCTs were conducted by the same group, were focused on respiratory infections, and used the same study design, consisting of 8 arms that compared all possible combinations of 3 strategies (audit and feedback, and 2 versions of CDSS) versus usual care.^52,53^ These RCTs reported inconsistent results, with 1 finding no differences in rates of inappropriate prescribing between the arms (3–4% for audit and feedback combined with CDSS vs 3% for usual care),^53^ and the other showing lower rates in the ASP arms (7–15% for audit and feedback plus CDSS vs 24% for usual care).^52^ However, both studies reported that there were no significant synergies between strategies, after conducting adjusted hierarchical random effects models. The third RCT on respiratory infections included 3 arms comparing combined audit and feedback and CDSS versus only audit and feedback versus usual care; this was conducted in 33 primary care practices in a large private health care system in the US, and reported lower antimicrobial prescribing rates for acute bronchitis in the combined program group (61%) versus usual care (74%).^54^ The RCT addressing urinary tract infections found increased rates of prescribing for first-line antibiotics but, as noted above, also higher overall rates for any antibiotic.^57^

#### Multicomponent Antimicrobial Stewardship Programs: Audit and Feedback and CDSS versus Audit and Feedback

Five studies on multicomponent programs reported the effects of combined audit and feedback and CDSS versus only audit and feedback on antimicrobial prescribing outcomes.^52–55,58^ All focused on respiratory infections. Only 2 studies assessed overall antimicrobial prescribing over 12–18 months; Hoye, 2013 reported an RCT conducted with 156 Norwegian general practices and found no differences between the combined program versus only audit and feedback (29% in both arms, p = 0.90).^55^ Colliers, 2023 described an observational study of 3 general practice cooperatives in Belgium (total of 579 general practitioners) that each implemented different antimicrobial stewardship programs. All 3 cooperatives carried out educational activities and audit and feedback, and 2 cooperatives also added EHR alerts or CRP testing, respectively.^58^ Only the cooperative implementing combined audit and feedback and EHR alerts observed a substantial change in rates (58% to 43% post-implementation), but it also had the highest prescribing rates at baseline (28–47% for the other 2 cooperatives).^58^

The 3 studies reporting on inappropriate antimicrobial prescribing were all RCTs, and 2 of these were the same trials described above that included 8 arms examining all possible combinations of audit and feedback and 2 versions of CDSS.^52,53^ Both trials reported lower rates of inappropriate prescribing in the combined program groups versus audit and feedback alone over 12 months (eg, 7% and 15% for the 2 versions of CDSS plus audit and feedback versus 19% for audit and feedback),^52^ but in adjusted hierarchical models there were no synergistic effects.^52,53^ The third RCT compared 3 arms over 6 months and was also described above; this reported lower rates in the combined program group (61%) compared with the audit and feedback only group (68%), but this was not statistically significant (p = 0.67).^54^

### Patient Outcomes and Health Care Utilization

Thirteen studies^14,28,31,32,34,38,41,44–47,52,54^ reported patient treatment outcomes (eg, adverse events) and/or health care utilization (eg, hospitalizations), and more than half evaluated audit and feedback versus usual care (k = 7). Other studies compared CDSS versus usual care (k = 4),^44–47^ or evaluated multicomponent ASP with CDSS and audit and feedback (k = 2).^52,54^ Patient treatment outcomes included infective complications, recurrent urinary tract infections, urosepsis, all-cause mortality, and adverse events.^14,28,31,38,41,45,46,52^ Studies generally found no differences in patient treatment outcomes between the intervention and comparator arms. For example, Livorsi, 2021 reported an IRR = 0.88, 95% CI [0.58, 1.34] when comparing all-cause mortality in the audit and feedback versus usual care arms.^31^ Madaras-Kelly, 2021 found no differences when comparing adverse events in the audit and feedback versus usual care arms at 12 months follow-up (OR = 0.93, 95% CI [0.6, 1.5], p = 0.77).^38^

Measures of health care utilization included hospital admission, repeat ER visits, and all-cause hospitalization.^28,31,32,34,38,44,45,47,54^ All 9 studies that reported measures of health care utilization found no difference between the intervention and comparator arms. For example, Livorsi, 2021 reported repeat ER visit adjusted IRR = 1.01, 95% CI [0.85, 1.19] and inpatient admission adjusted IRR = 1.01, 95% CI [0.81, 1.27] at 12 months of follow-up.^31^ Madaras-Kelly, 2021 assessed return visits related to respiratory tract infections and hospitalizations, finding OR = 1.03, 95% CI [0.79, 1.34], p = 0.84 and OR = 0.93, 95% CI [0.58, 1.5], p = 0.77, respectively.^38^

### Staff Satisfaction and Acceptability

Five studies reported measures of staff satisfaction and acceptability.^14,26,29,58,59^ Three studies^14,26,29^ evaluated audit and feedback, while the other 2 studies addressed multicomponent ASPs.^58,59^ Four of the studies^14,26,29,59^ were RCTs and 1 was observational^58^; four^14,26,58,59^ were conducted in Europe and the fifth^29^ in Canada. Authors surveyed participants regarding different components of the stewardship strategy or program, including the clinical and patient education aspects, audit and feedback, CDSS, and/or other components. Regarding audit and feedback, several studies reported that participants found the feedback to be useful.^26,29,61^

Two studies reported staff concerns regarding the increased time burden to perform additional tasks, primarily in regards to incorporating patient or clinician education.^61,62^ For example, Poss-Doering, 2020a stated:

Medical assistants felt pressured to make time for dealing with the tablets… [This] intervention component represented an additional task they felt responsible for…[T]he value of tablets as an information tool did not justify investing the scarce resource of time into efforts of briefing patients about the proper usage of the devices.^62^

One of these studies also noted that reimbursements could impact adoption of certain components:

…[Physicians] considered incentivization of documentation as well as consultation activities necessary to foster guideline-oriented prescribing sustainably. Using C-reactive protein testing was considered to provide safety for decision-making and thus physicians thought it should be reimbursed by health insurers.^61^

### Implementation Costs and Barriers

Two studies reported costs of antibiotics prescribed; both were RCTs comparing audit and feedback with usual care.^23,41^ One was conducted in Canada^23^ and the other in the UK.^41^ The Canadian study reported 6.1% reduction in costs associated with antibiotic prescriptions (OR = 0.94, 97.5% CI [0.89, 0.99], p = 0.01) in favor of audit and feedback. They estimated savings of $771 per primary care physician over the 12-month study period.^23^ The UK study reported that there were no differences, with the audit and feedback arm having 92% of costs in the usual care arm (95% CI [79%, 107%], p = 0.30).^41^

Four studies,^14,58,59,63^ 2 RCTs and 2 observational, summarized themes on barriers and facilitators from surveys and interviews of participants. All four trials were conducted in Europe. Three studies^18,58,59^ evaluated the implementation of multicomponent ASPs. All studies included audit and feedback and clinician and patient educational components. Surveys and interviews mainly focused on the audit and feedback and educational components. Consistent themes across the 4 studies, particularly regarding educational components of antimicrobial stewardship strategies, included variable incorporation or engagement with educational components, increased competition for time and resources, and adaptability and flexibility of educational materials and formats (see Supplementary Materials).

The following are examples of comments on engagement or incorporation of ASP components:

Highest barriers were seen in integrating tablet (portable electronics) devices [with] 50% of medical assistants anticipated high effort.^61^

Engagement with…website engagement being poor. Lack of time and competing priorities in general practice were frequently cited as reasons for low engagement.^18^

Survey and interview responses often note the need for additional monetary resources and challenges competing priorities for limited time:

…[P]hysicians alluded to financial losses if consultation times constantly expanded.^61^

…[I]nternal support by the [General Practice Cooperative] board and external support by…an academic partner, … the necessary budget and a local champion who can move it forward with enough time, are essential for the sustainability of the implementation.^58^

Study authors reported varying concerns about compatibility and flexibility of components:

Major compatibility concerns were voiced with regard to offering devices in waiting areas… Others were willing to adopt the provision tablets but observed a widespread patient disinterest… Practical concerns were voiced in a general fear of theft of high value electronic devices and in hygiene issues… Analog patient information material was reported to have a very high acceptance.^61^

### Reach: Prescribers and Clinics

Four studies^37,46,48,64^ reported on reach among clinicians; 2 studies compared audit and feedback with usual care,^37,64^ and 2 studies evaluated CDSS.^46,48^ Curtis, 2021 sent short written feedback by email or fax/mail every 5 weeks, with all materials including a personalized link to online individual dashboards; accessing these dashboards was similarly infrequent for both groups (25–26% of participants).^37^ Poss-Doering, 2020b conducted a process evaluation and concluded:

Uptake… was heterogenous. Across all components, the uptake reported by General Practitioners varied from 20 to 88% [for clinician education and feedback] and 31 to 63% [for ordering of patient education materials and toys]…^64^

The 2 studies evaluating CDSS both assessed engagement with CDSS tools or alerts. Guilford, 2014 reported 63 views per 1,000 visits for respiratory infections,^46^ and Mann, 2020 indicated that the tool was completed only 6.9% (out of 42,126 total times it was activated); the low uptake was observed for both sites in the latter study.^48^ McGinn, 2013 noted that the CDSS tool was opened during 63% of the visits when it was triggered, and the recommended order sets were completed during 42% of those visits.^44^