# METHODS

## TOPIC DEVELOPMENT

We defined the scope, formulated key questions, and determined eligibility criteria for study selection in collaboration with the operational partners and members of our technical expert panel (TEP). We defined an ASP or strategy as any systematic activity with the expressed intent of impacting antimicrobial prescribing. To address the broad scope and objectives of this project, we conducted an evidence map to identify and describe the state of the current evidence (including evidence gaps) on ASP and strategies in outpatient settings. After identifying all eligible studies, we used preliminary findings to further engage the partners and TEP in developing prioritization criteria to select a subset for abstraction and synthesis of detailed findings (see section below on prioritization).

## REGISTRATION AND REVIEW

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (CRD42024603377 (https://www.crd.york.ac.uk/PROSPERO/view/CRD42024603377)). A draft version of this report was reviewed by external peer reviewers; their comments and author responses are provided in the Supplementary Materials.

## KEY QUESTIONS AND ELIGIBILITY CRITERIA

The following key questions were the focus of this review:

- Key Question 1 (KQ1): What are the characteristics of studies that have evaluated antimicrobial stewardship programs or strategies focused on antimicrobial prescribing?
- Key Question 2 (KQ2): For prioritized studies (based on settings and/or type of programs or strategies), what are the reported outcomes associated with implementation of antimicrobial stewardship programs or strategies?

Study eligibility criteria are shown in the table below:

Domain | Eligibility Criteria
Population | Adults (≥ 18 years old, include if mean age or majority ≥ 18)
Intervention | Antimicrobial stewardship programs or strategies focused on improving antimicrobial prescribing (eg, clinician education, audit and feedback, public health campaigns, clinical decision support systems, systematic efforts meeting Center for Disease Control and Prevention’s (CDC)^4^ core elements for outpatient antimicrobial settings, delayed prescribing, etc)
Comparator | Any
Outcomes * | Reach: type and proportion of patients, community members impacted, type and proportion of providers and facilities; Effectiveness: patient outcomes (eg, acceptability, satisfaction, infections successfully treated, adverse events), health care utilization (return clinic visits, emergency room visits, hospital admissions), microbial resistance in the community; Adoption: changes in antimicrobial prescribing, alignment with clinical guidelines; Implementation: costs, staff outcomes (eg, acceptability, satisfaction, burn out), other barriers/facilitators; Maintenance: costs, sustainability (minimum of 12 months)
Timing | ≥ 6 months
Setting | Outpatient clinics, emergency rooms, urgent care; Countries that are members of the Organisation for Economic Co-operations and Development (OECD)^6^
Study Design | Randomized controlled trials; Observational studies; Systematic reviews

Notes.

* Organized according to the RE-AIM framework.^7^

## SEARCHING AND SELECTION

To identify articles relevant to the key questions, a research librarian searched Ovid MEDLINE, Ovid Embase, and Scopus from January 1, 2013 through September 3, 2024 using key words and subject headings for antimicrobial prophylaxis, drug resistance, antimicrobial stewardship, guideline adherence, evaluation, and specific ASP strategies (eg, audit and feedback, clinical decision support system; see Appendix). Additional citations were identified from hand-searching reference lists and consultation with content experts.

After duplicates were removed, citations were uploaded into DistillerSR (Evidence Partners, Ottawa, Canada). Abstracts were screened in 2 phases, with the assistance of DistillerSR’s Artificial Intelligence System (DAISY). In the first phase, abstracts were excluded only if 2 independent reviewers agreed on exclusion; 10,441 abstracts were screened, until the remaining studies had predicted likelihood for inclusion ≤ 0.1. At this point, the inclusion rate for the most recently screened ~2,300 articles had been < 1%. In the second phase, a single human reviewer screened an additional 6,368 abstracts for inclusion; no eligible article was identified during this additional screening. The remaining 43% of abstracts (12,729) were not examined by a human reviewer. DAISY predictions indicated we may have missed 4 articles for inclusion by not further reviewing the remaining abstracts.

For full-text review, 2 reviewers independently examined the article and decided on eligibility. Inclusion and exclusion required consensus of both reviewers, which was either reached via discussion or involvement of a third reviewer. We undertook an initial pilot round to further clarify and operationalize the inclusion and exclusion criteria.

## PRIORITIZATION OF STUDIES FOR SYSTEMATIC REVIEW

We developed prioritization criteria collaboratively with the TEP using a 2-step process. First, we presented the preliminary evidence map findings to operational partners and the TEP and encouraged group discussion of priorities for understanding the evidence for various ASPs/strategies conducted in different settings, and the rationale for these priorities. After this meeting, we then conducted individual online surveys to collect data on forced ranking of the top 3 ASP or strategies, and the top 3 settings. Studies were then prioritized based on the following criteria: conducted in primary care, ER/urgent care, and/or general outpatient setting; investigated audit and feedback, EHR-based CDSS, or multicomponent ASPs; and either an RCT or observational study with at least 1 concurrent comparator (Figure 1).

Figure 1 Prioritization of Eligible Studies from Evidence Map

Notes. *Tools integrated in the electronic health record with computer order entry.

^†^Includes 2 or more strategies in addition to patient and/or clinician education.

Diagram outlining prioritization of studies based on criteria focused on primary care, emergency room/urgent care, and/or general outpatient setting; audit and feedback, EHR-based CDSS, or multicomponent antimicrobial stewardship programs; and either an RCT or observational study with at least 1 concurrent comparator.

## DATA ABSTRACTION AND RISK OF BIAS ASSESSMENT

For all eligible studies included in the evidence map, we abstracted the following information: study design, population, setting, intervention, and reported outcomes. For prioritized studies, we further abstracted detailed findings for eligible outcomes (eg, effect measures, interview quotes) and additional information on the clinical population(s), ASP or strategy, and comparator characteristics. All data abstraction was first completed by 1 reviewer and then checked by a second reviewer.

For prioritized studies only, we also completed assessments of internal validity using the Cochrane Risk of Bias (RoB) 2.0 for RCTs, or Newcastle-Ottawa tools for observational studies.^8,9^ Internal validity ratings were independently conducted by 2 reviewers, and disagreements were resolved by consensus or discussion with a third reviewer (see Supplementary Materials for detailed ratings).

## SYNTHESIS

In the evidence map of all eligible primary studies and systematic reviews, we summarize study characteristics using descriptive figures and tables. We categorized primary studies by types of ASPs and strategies, and for systematic reviews, we identified the types of strategies that met eligibility for these reviews (as these often included multiple types of ASPs and strategies). Because patient and/or clinician education was included in nearly every primary study, we first determined if the study only evaluated patient and/or clinician education to improve antimicrobial prescribing, or if there was another specific strategy employed (eg, audit and feedback). If there was only 1 additional specific strategy, we indicated which of the following was used: 1) audit and feedback, 2) CDSS (embedded in EHR), 3) laboratory tests, 4) pharmacist review, 5) public health campaigns, 6) focus on delayed prescribing, 7) pay for performance, or 8) formulary policy changes. For multicomponent ASPs that involved 2 or more of these specific strategies (in addition to patient and/or clinician education), we separately describe the number and types of strategies involved.

We also describe the outcomes reported by eligible primary studies, and the outcomes of interest for eligible systematic reviews. We used the RE-AIM^7^ framework to help identify and define the most relevant outcomes for evaluating the impact of ASPs or strategies. Under Reach, we focused on the type and proportion of patients, community member impacted, in addition to the type and proportion of prescribers, sites and facilities involved. For effectiveness, we considered mainly patient outcomes, including resolution of clinical conditions, acceptability or satisfaction with treatments, adverse events, and health care utilization (return clinic visits, ER visits, hospital admissions). We also included changes in microbial resistance in the community as part of the effectiveness of ASPs. For adoption, we selected changes in overall antimicrobial prescribing and alignment with clinical guidelines (whether score-based or counts of appropriate/inappropriate prescribing), as these were common measures of the desired changes in clinical practice. We also included implementation costs, staff outcomes (eg, acceptability, satisfaction, burnout), and other barriers/facilitators to help understand the implementation process. Finally, we indicated whether studies reported longer-term data on maintenance costs and sustainability of effects (≥ 1 year from start date and presented as a distinct phase from initial implementation).

For the prioritized studies, we conducted quantitative meta-analysis when there were ≥ 3 studies that were sufficiently similar in ASPs or strategies and comparator groups, and evaluated outcomes in similar manner (eg, comparable measures of antibiotic prescribing) with sufficient follow-up (a minimum of 12 months). Otherwise, we provide qualitative syntheses of study characteristics and findings. For meta-analyses, we used a random-effects model (with Hartung-Knapp-Sidik-Jonkman estimator) due to the anticipated heterogeneity in effects arising from variation in patient populations, clinical settings, and other study characteristics. We assessed statistical heterogeneity with the use of forest plots, τ^2^, and 95% prediction intervals (PIs). PIs describe the most likely range of true effects (eg, true differences in antibiotic prescribing change between intervention and control groups) across the included studies and provide an estimate of the magnitude and direction in potential future studies. PIs encompassing values similar to the pooled point estimate suggest limited heterogeneity, whereas PIs encompassing estimates that range widely in both magnitude and direction indicate substantial heterogeneity. We were unable to assess publication bias using funnel plots since we did not identify ≥ 10 sufficiently similar studies (according to considerations described previously). We used meta and metafor (https://cran.r-project.org/web/packages/metafor/index.html) packages and for R (R Foundation for Statistical Computing, Vienna, Austria) version 4.4.2 to conduct meta-analyses and generate forest plots.^10^

### Certainty of Evidence

We did not rate the certainty of evidence.