# BACKGROUND

Antimicrobial stewardship programs (ASP) seek to improve antimicrobial prescribing practices, optimize patient outcomes, and reduce antimicrobial resistance. For patients, more appropriate prescribing should lead to lower morbidity and mortality from infectious conditions and fewer adverse events related to antimicrobial overuse. For communities, better prescribing can prevent higher levels of antimicrobial resistance, which is currently estimated to cause 5 million additional deaths per year globally.^1^ Growing antimicrobial resistance, such as increasing occurrence of extended spectrum beta lactamase (ESBL) expression in gram-negative bacteria, leave patients with fewer antimicrobial options, increased drug toxicity, and increased mortality.

More than 80% of antimicrobial usage occurs in the outpatient setting, including primary care clinics, dental clinics, emergency rooms (ER), urgent care, and other sites.^2^ Furthermore, nearly 30% of antibiotics prescribed in the outpatient setting may be inappropriate or unnecessary.^2,3^ Outpatient ASPs have unique challenges, including the need to tailor strategies for clinics with varying resources and a diversity of clinical populations. Similar to other efforts to improve clinical practice, specific barriers to change also include patient expectations and priorities, decreasing time for clinical visits, and greater administrative burden for clinicians. Understanding which strategies have been effective and the implementation process for these will be critical for optimizing ASPs and planning future implementation efforts.

The Centers for Disease Control and Prevention (CDC) has outlined 4 core elements of outpatient antibiotic stewardship: 1) commitment by clinicians and health care leadership, 2) action through implementation of at least 1 policy or practice, 3) tracking of prescribing and feedback of these data to prescribers, and 4) patient and clinician education on appropriate antimicrobial prescribing.^4^ These core elements were modeled on frameworks for health care quality improvement and intended to be flexible for tailoring to individual clinical settings. It is currently unclear if outpatient ASPs following these core elements would be more successful at improving antimicrobial prescribing practices. Additionally, specific strategies may be more impactful when used alone or in combination with other strategies within an ASP. These include clinical decision support systems (CDSS) embedded in electronic health records (EHR) with computerized order entry, and practices such as delayed prescribing.^4^

To inform efforts to develop implementation strategies and improve outpatient ASP for VHA clinics and facilities, the VA National Antimicrobial Stewardship Taskforce and the VHA National Infectious Disease Service requested an update to the prior evidence review conducted by the VA Evidence Synthesis Program in 2013.^5^ We conducted an evidence map to describe evidence (published since 2013) on the effects and implementation processes of ASP strategies and programs in outpatient settings. We also present the results of a systematic review of a prioritized set of eligible studies that were conducted in primary care and ER or urgent care settings.