# Appendix

## SEARCH STRATEGIES

### MEDLINE (1946 TO SEPTEMBER 03, 2024)

# | Search Statement | Results
1 | Antibiotic Prophylaxis/ or exp anti-bacterial agents/ or anti-infective agents, urinary/ | 855085
2 | (antibacteri* or anti-bacteri* or antibiotic* or antimicrob* or anti-microb* or (anti-infective* adj3 urinary)).ti,ab,kf. | 706676
3 | exp Aminoglycosides/ or exp Carbapenems/ or exp Carbapenem-Resistant Enterobacteriaceae/ or exp Cephalosporins/ or exp Fluoroquinolones/ or Methicillin-Resistant Staphylococcus aureus/ or Vancomycin/ or Vancomycin-Resistant Staphylococcus aureus/ or Vancomycin-Resistant Enterococci/ | 294357
4 | (aminoglycoside? or carbapenem? or cephalosporin? or fluoroquinolone? or vancomycin?).ti,ab,kf. | 111077
5 | exp Drug Resistance, Bacterial/ or drug resistan* bacteria?.ti,ab,kf. or beta-lactam* resistan*.ti,ab,kf. | 111381
6 | or/1-5 | 1337123
7 | Antimicrobial Stewardship/ or ((antibacteri* or anti-bacteri* or anti-infecti* or antimicrobial? or anti-microbial? or bacteria* or aminoglycoside? or beta-lactam* or broad spectrum* or carbapenem? or cephalosporin? or fluoroquinolone? or vancomycin?) adj3 steward*).ti,ab,kf. | 9852
8 | (Education/ or exp Curriculum/ or exp Health Education/ or exp Education, Professional/ or Formative Feedback/ or Interdisciplinary Placement/ or exp Inservice Training/ or Interprofessional Education/ or Staff Development/ or exp Professional Competence/ or ed.fs.) not Education, Veterinary/ | 841356
9 | ((clinic* or nurse? or nursing or pharmac* or physician or practitioner? or professional or provider?) adj3 (educat* or feedback or inservice? or outreach or perspective? or teach* or train*)).ti,ab,kf. | 196772
10 | decision making, computer-assisted/ or decision support systems, clinical/ or exp electronic health records/ or drug therapy, computer-assisted/ or Electronic Prescribing/ or medical order entry systems/ or medical records systems, computerized/ or Point-of-Care Systems/ or Point-of-Care Testing/ or reminder systems/ or ((computer* or electronic* or EHR or internet or online or system? or web-based) adj3 (assist* or decision* or nudge? or order? or prescrib* or prescrip* or prompt? or reminder? or record? or support or tool?)).ti,ab,kf. or (point adj2 care).ti,ab,kf. | 280202
11 | exp Clinical Decision-Making/ or Decision-Making/ or ((clinic* adj2 support*) or “decision making” or “decision support*” or “expert* system?”).ti,ab,kf. | 345276
12 | Drug Prescriptions/ or ((direction? or directive?) adj3 (prescrib* or prescrip*)).ti,ab,kf. | 31552
13 | Drug Utilization Review/ or drug utili?ation review?.ti,ab,kf. or drug utili?ation evaluation.ti,ab,kf. | 4338
14 | exp Clinical Audit/ or Management Audit/ or (audit or audits or auditing).ti,ab,kf. | 62630
15 | Guideline Adherence/ or Guidelines as Topic/ or Practice Guidelines as Topic/ or ((guideline? or pathway? or protocol? or recommend? or requirement? or standard*) adj3 (adherence or concordance or implement* or practice?)).ti,ab,kf. | 280108
16 | Inappropriate Prescribing/ or ((appropriate* or decrease* or de-escalat* or inappropriate* or unnecessary) adj3 prescrib*).ti,ab,kf. | 10908
17 | Consumer Health Information/ or Health Communication/ or Information Dissemination/ or exp “Marketing of Health Services”/ or Patient Education as Topic/ or Patient Medication Knowledge/ or ((consumer? or patient? or public) adj3 (awareness or communication or educat* or informational* or literacy or perspective? or teach*)).ti,ab,kf. or (campaign* or marketing).ti,ab,kf. or (information* adj2 disseminat*).ti,ab,kf. or (patient* adj3 knowledg*).ti,ab,kf. | 364695
18 | interdisciplinary communication/ or Interprofessional Relations/ or Leadership/ or ((inter-disciplin* or interdisciplin* or inter-profession* or interprofession* or multidisciplin* or transdisciplin*) adj3 (communicat* or leadership or management or relation*)).ti,ab,kf. | 129782
19 | Medication Review/ or exp medication systems/ or (medication adj3 (reconciliation or review* or system?)).ti,ab,kf. | 13486
20 | Patient Discharge/ or ((hospital* or patient?) adj2 discharg*).ti,ab,kf. | 120857
21 | Physician Incentive Plans/ or Prior Authorization/ or Reimbursement Mechanisms/ or ((physician or reimburse*) adj3 incent*).ti,ab,kf. or (preauthorization or pre-authorization or prior authorization?).ti,ab,kf. | 17402
22 | Practice Patterns, Nurses’/ or Practice Patterns, Pharmacists’/ or Physician’s Practice Patterns/ or (prescrib* adj3 practice?).ti,ab,kf. | 76351
23 | Program Evaluation/ or Quality Improvement/ or (quality adj3 improve*).ti,ab,kf. or ((intervention* or program*) adj3 (effectiveness or evaluat* or implement*)).ti,ab,kf. | 409232
24 | or/7-23 | 2509285
25 | and/6,24 | 64354
26 | 25 not (exp animals/ not humans.sh.) | 62719
27 | 26 not (exp infant/ or exp child/ or adolescent/) not exp adult/ | 36972
28 | 27 not (animal or bovine or canine or cattle or chicken? or cow or cows or farm or farms or horse? or livestock or mice or mouse or murine or pig or pigs or piglet? or porcine or poultry or rabbit? or sheep or swine or veterinary or veterinarian? or child or children or infant? or neonatal or p?ediatric*).jn,ti. | 35262
29 | 28 not (case reports/ or comment/ or editorial/ or letter/ or news/ or study guide/) | 31638
30 | limit 29 to (english language and yr=“2013 -Current”) | 19964
31 | exp randomized controlled trial/ | 622463
32 | controlled clinical trial/ | 95599
33 | exp clinical trial/ | 1003355
34 | (clin$ adj3 trial$).ti,ab,kw. | 564769
35 | Drug Therapy.fs. | 2730915
36 | groups.ab. | 2729886
37 | controlled trial.ti,ab,kw. | 189281
38 | ((singl$ or doubl$ or trebl$ or tripl$) adj25 (blind$ or mask$)).ti,ab,kw. | 218499
39 | Placebos/ | 35994
40 | placebo$.ti,ab,kw. | 260614
41 | random$.ti,ab,kw. | 1553468
42 | (Observational Study or Clinical Study).pt. | 167140
43 | (observational adj3 (study or studies or design or analysis or analyses)).ti,ab,kf. | 252938
44 | (cohort* adj3 (study or studies or design or analysis or analyses)).ti,ab,kf. | 444939
45 | (prospective adj7 (study or studies or design or analysis or analyses)).ti,ab,kf. | 576869
46 | ((follow up or followup) adj7 (study or studies or design or analysis or analyses)).ti,ab,kf. | 182920
47 | ((longitudinal or longterm or (long adj term)) adj7 (study or studies or design or analysis or analyses or data)).ti,ab,kf. | 379796
48 | (quasi adj (experiment or experiments or experimental)).ti,ab,kf. | 23379
49 | organizational case studies/ or ((institution* or organization*) adj3 (evaluation or study)).ti,ab,kf. | 36291
50 | Interrupted Time Series Analysis/ or ((segment$2 adj3 regression) or time* series or slope change or ((piecewise or piece-wise) adj3 regression)).tw,kf. or ((implement* or rates) and (((pre or before or prior) adj5 (post or after or follow*)) or quasi-experiment* or quasiexperiment* or natural experiment* or ARIMA or autoregress* or auto-regress* or integrat* moving average or segmented or segments or piecewise or piece-wise)).tw,kf. | 155488
51 | exp Empirical Research/ or Interviews as Topic/ or Focus Groups/ or Narrative Medicine/ or Research Design/ or “Surveys and Questionnaires”/ or (focus group? or hybrid design or interview* or grounded theory or mixed method? or purposiv* sampling or qualitativ* or survey* or theme?).ti,ab. or ((concept* or data or thematic or theoretical) adj2 saturat*).ti,ab. | 2117965
52 | or/31-51 | 9036353
53 | 30 and 52 | 10782
| Total | 10,782

### EMBASE (1974 TO 2024 WEEK 35)

# | Search Statement | Results
1 | antibiotic prophylaxis/ or antibiotic therapy/ or antimicrobial therapy/ or exp urinary tract antiinfective agent/ or (antibacteri* or anti-bacteri* or antibiotic* or antimicrob* or anti-microb* or (anti infective* adj2 urinary)).ti,ab,kf. | 1123747
2 | exp antibiotic resistance/ or Methicillin-Resistant Staphylococcus aureus/ or beta-lactam* resistan*.ti,ab,kf. or drug resistan* bacteria*.ti,ab,kf. | 273839
3 | ((aminoglycoside? or carbapenem? or cephalosporin? or fluoroquinolone? or vancomycin*) adj3 (therap* or treatment or prescrib* or prescrip* or resistan*)).ti,ab,kf. | 55726
4 | or/1-3 | 1206182
5 | 5 antimicrobial stewardship/ or ((antibacteri* or anti bacteri* or antibiotic? or anti infecti* or antimicrobial* or anti microbial*) adj3 steward*).ti,ab,kf. | 20031
6 | (Clinical education/ or interdisciplinary education/ or interprofessional education/ or continuing education/ or curriculum/ or in service training/) not veterinary education/ | 174065
7 | ((clinic* or interdisciplinary or interprofessional or nurse? or nursing or pharmac* or physician or practitioner? or professional or provider?) adj3 (educat* or feedback or inservice? or outreach or perspective? or teach* or training)).ti,ab,kf. | 238941
8 | computerized provider order entry/ or electronic health record/ or electronic prescribing/ or expert system/ or physician order entry system/ or “point of care system”/ or reminder system/ or ((computer* or electronic* or EHR or internet or online or web-based) adj3 (assist* or decision* or nudge? or order? or prescrib* or prescrip* or prompt? or reminder? or record? or support or tool?)).ti,ab,kf. or (point adj care).ti,ab,kf. | 259076
9 | clinical decision making/ or medical decision making/ or (clinical support or decision making or decision support* or expert* system?).ti,ab,kf. | 451968
10 | prescription drug/ or ((direction? or directive?) adj5 (prescrib* or prescrip*)).ti,ab,kf. | 14584
11 | “drug utilization review”/ or drug utili?ation review*.ti,ab,kf. | 3002
12 | clinical audit/ or (audit or audits or auditing).ti,ab,kf. | 113374
13 | practice guideline/ or prescribing guideline/ or professional standard/ or ((guideline? or pathway? or protocol? or recommend? or requirement? or standard*) adj3 (adherence or concordance or implement* or practice?)).ti,ab,kf. | 743286
14 | unnecessary prescribing/ or ((appropriate* or decrease* or de-escalat* or inappropriate* or unnecessary) adj3 prescrib*).ti,ab,kf. | 12465
15 | consumer health information/ or health education/ or health literacy/ or health promotion/ or information dissemination/ or patient education/ or public health message/ or public health campaign/ or social marketing/ or ((consumer? or patient? or public) adj3 (awareness or campaign* or communication or educat* or informational* or literacy or marketing or teach*)).ti,ab,kf. or information dissemination.ti,ab,kf. or (patient adj3 knowledg*).ti,ab,kf. | 534696
16 | interdisciplinary communication/ or ((inter-disciplin* or interdisciplin* or inte-rprofession* or interprofession* or multidisciplin* or transdisciplin*) adj3 (communicat* or leadership or management or relation*)).ti,ab,kf. | 35741
17 | medication systems/ or (medication adj3 (reconciliation or review* or system?)).ti,ab,kf. | 17670
18 | hospital discharge/ or ((hospital* or patient?) adj2 discharg*).ti,ab,kf. | 289667
19 | prior authorization/ or reimbursement/ or ((physician? or reimburse*) adj2 incent*).ti,ab,kf. or (preauthorization or pre-authorization or prior authorization?).ti,ab,kf. | 72614
20 | clinical practice/ or nursing practice/ or pharmacy practice/ or prescribing practice/ or (prescrib* adj3 practice?).ti,ab,kf. | 414544
21 | program evaluation/ or quality improvement/ or (quality adj3 improve*).ti,ab,kf. or ((intervention* or program*) adj3 (effectiveness or evaluat* or implement*)).ti,ab,kf. | 517759
22 | or/5-21 | 3219552
23 | 4 and 22 | 118702
24 | limit 23 to (english language and yr=“2013 -Current”) | 83625
25 | 24 not ((exp animal/ or animal experiment/ or nonhuman/) not (human/ or human experiment/)) | 79927
26 | (animal or animals or rat or rats or mouse or mice or swine or porcine or murine or sheep or lambs or pigs or piglets or rabbit or rabbits or cat or cats or dog or dogs or cattle or bovine or monkey or monkeys or trout or veterinar*).ti,jx. | 2808899
27 | 25 not 26 | 79058
28 | 27 not (exp juvenile/ not exp adult/) | 69783
29 | 28 not (child or children or infant? or neonatal or neonate or p?edatric?).ti,jx. | 68476
30 | limit 29 to (books or chapter or conference abstract or conference paper or “conference review” or editorial or letter or “preprint (unpublished, non-peer reviewed)”) | 25456
31 | 29 not 30 | 43020
32 | 31 not (book/ or exp conference paper/ or editorial/ or letter/) | 42924
33 | limit 32 to (book or book series or conference proceeding or “preprint archive (unpublished, non-peer reviewed)”) | 37
34 | 32 not 33 | 42887
35 | exp clinical trial/ or exp “clinical trial (topic)”/ | 2385697
36 | control group/ or crossover procedure/ or double blind procedure/ or Placebos/ or randomization/ or single blind procedure/ | 774511
37 | (random* or sham or placebo*).ti,ab. | 2340271
38 | ((singl* or doubl*) adj (blind* or dumm* or mask*)).ti,ab,kf. | 293281
39 | ((tripl* or trebl*) adj (blind* or dumm* or mask*)).ti,ab,hw,kf. | 2488
40 | (control* adj3 (study or trial* or group*)).ti,ab,kf. | 1761965
41 | (clinical adj3 (study or studies or trial*)).ti,ab,kf. | 1210538
42 | (Nonrandom* or non random* or non-random* or quasi-random* or quasirandom*).ti,ab,hw,kf. | 75487
43 | (phase adj3 (study or trial*)).ti,ab,kf. | 275756
44 | ((crossover or cross-over) adj3 (study or studies or trial*)).ti,ab,hw,kf. | 72797
45 | ((multicent* or multi-cent*) adj3 (study or studies or trial*)).ti,ab,kf. | 282684
46 | allocated.ti,ab,hw. | 117422
47 | ((open label or open-label) adj5 (study or studies or trial*)).ti,ab,kf. | 94427
48 | ((equivalence or superiority or non-inferiority or noninferiority) adj3 (study or studies or trial*)).ti,ab,hw,kf. | 20611
49 | (pragmatic study or pragmatic studies).ti,ab,hw,kf. | 1048
50 | ((pragmatic or practical) adj3 trial*).ti,ab,hw,kf. | 9882
51 | ((quasiexperimental or quasi-experimental) adj3 (study or studies or trial*)).ti,ab,hw,kf. | 22231
52 | trial.ti. | 435601
53 | or/35-52 | 5424513
54 | cohort analysis/ or comparative effectiveness/ or comparative study/ or multimethod study/ or observational study/ or quasi experimental study/ or time series analysis/ | 2691683
55 | comparative study/ or comparative effectiveness/ | 1227438
56 | exp observational method/ | 7592
57 | pretest posttest control group design/ or pretest posttest design/ | 11180
58 | cross-sectional study/ or follow up/ or longitudinal study/ or prospective study/ or quasi experimental study/ or retrospective study/ | 4858585
59 | (observational adj3 (study or design or analysis or analyses)).ti,ab,kf. | 328352
60 | (prospective adj5 (study or studies or design or analysis or analyses)).ti,ab,kf. | 853378
61 | ((follow up or followup) adj5 (study or studies or design or analysis or analyses)).ti,ab,kf. | 230989
62 | ((longitudinal or longterm or (long adj term)) adj5 (study or studies or design or analysis or analyses or data)).ti,ab,kf. | 469410
63 | (retrospective adj5 (study or studies or design or analysis or analyses or data)).ti,ab,kf. | 1083669
64 | (cross adj sectional adj5 (study or studies or design or research or analysis or analyses or survey or findings)).ti,ab,kf. | 641972
65 | ((multicent* or multi-cent*) adj3 (study or studies)).ti,ab,kf. | 217439
66 | ((segment$2 adj3 regression) or time* series or slope change or ((piecewise or piece-wise) adj3 regression) or ((implement* or rates) and (((pre or before or prior) adj5 (post or after or follow*)) or quasi-experiment* or quasiexperiment* or natural experiment* or ARIMA or autoregress* or auto-regress* or integrat* moving average or segmented or segments or piecewise or piece-wise))).tw,kf. | 227142
67 | mixed method?.tw. | 55242
68 | exp qualitative research/ or exp interview/ or (focus group? or interview* or purposiv* sampling or qualitativ* or theme? or ((concept* or data or thematic or theoretical) adj2 saturat*)).ti,ab. | 1150252
69 | or/54-68 | 8075521
70 | 53 or 69 | 11547567
71 | 34 and 70 | 25144
| Total | 25,144

### SCOPUS (SEPTEMBER 05, 2024)

# | Search Statement | Results
1 | KEY(“anti-bacterial agents” OR “antibacterial therap*” OR “antibiotic prophylaxis” OR “antibiotic therap*” OR “antimicrobial therap*” OR “antibiotic resistan*” OR (anti-infective W/3 urinary) OR (bacteria* W2 drug resistan*) OR “beta-lactam* resistanc*” OR (broad spectrum W/3 resistan*)) OR TITLE-ABS-KEY(antibacterial therap* OR antibiotic prophylaxis OR antibiotic therap* OR antibiotic* use OR antibiotic resistan* OR antibiotic* utilization OR antimicrobial therap* OR beta-lactam* resistanc* OR (broad spectrum W/3 resistan*)) OR TITLE-ABS-KEY(aminoglycoside* W/3 (therap* OR treatment OR prescrib* OR prescrip* OR resistan*)) OR TITLE-ABS-KEY(carbapenem* W/3 (therap* OR treatment OR prescrib* OR prescrip* OR resistan*)) OR TITLE-ABS-KEY(cephalosporin* W/3 (therap* OR treatment OR prescrib* OR prescrip* OR use OR resistan*)) OR TITLE-ABS-KEY(fluoroquinolone W/3 (therap* OR treatment OR prescrib* OR prescrip* OR use OR resistan*)) OR TITLE-ABS-KEY(vancomycin* W/3 (therap* OR treatment OR prescrib* OR prescrip* OR use OR resistan*)) AND KEY(antibacterial W/3 steward*) OR KEY(antimicrobial W/3 steward*) OR KEY(antibiotic W/3 steward*) OR TITLE-ABS-KEY(antimicrobial W/3 steward*) OR TITLE-ABS-KEY(antibacterial W/3 steward*) OR TITLE-ABS-KEY(antibiotic* W/3 steward*) OR SRCTITLE(Antimicrobial Stewardship) OR KEY(audit OR “clinic* educat*” OR “clinic* support*” OR “consumer health*” OR curriculum OR “decision-making” OR “decision support system*” OR “drug utilization review” OR education OR “electronic health record” OR feedback OR “guideline adherence” OR “Guidelines as Topic” OR “health education” OR “hospital discharge” OR (inappropriat* W/3 prescrib*) OR “information dissemination” OR “Interprofessional Relations” OR “Marketing of Health Services” OR “in service training” OR “interdisciplinary communication” OR “interprofessional education” OR “Interprofessional relations” OR leadership OR “Marketing of Health Services” OR “Medication Review” OR “medication system” OR “nurs* educat*” OR “order entry system*” OR “clinical pathway” OR (patient W/3 education) OR “Patient Education as Topic” OR “patient knowledge” OR “Patient Medication Knowledge” OR “pharm* educat*” OR “Physician Incentive Plans” OR “point of care system” OR (prescrib* W/3 de-escalat*) OR “prescribing practices” OR “prescribing guideline” OR (practice patterns W/2 nurses’) OR (practice patterns W/3 pharmacists’) OR (practice patterns W/2 physicians’) OR “prior authorization” OR “professional competence” OR protocol OR (professional W/2 education) OR “professional standard” OR “public health campaign” OR (program W/3 evaluation) OR (quality W/3 improvement) OR “reimbursement” OR “reminder system” OR “marketing” OR (unnecessary W/3 prescrib*) OR “staff development”) OR TITLE-ABS(audit* OR (clinic* W/3 educat*) OR (clinic* W/3 support*) OR campaign OR “consumer health*” OR “decision-making” OR “decision support system*” OR “drug utilization review” OR “electronic health record” OR feedback OR (guideline W3 adherence) OR “hospital discharge” OR (information W/2 dissemination) OR “interdisciplinary communication” OR “in service training” OR leadership OR marketing OR “medication system” OR (nurs* W/3 educat*) OR “order entry system*” OR “clinical pathway” OR (patient W/3 education) OR (patient W/3 knowledge) OR (pharm* W/2 educat*) OR (physician W/3 education) OR (physician W/3 incentiv*) OR “point of care system” OR (prescribing W/3 practices) OR (prescribing W/3 guideline) OR “prior authorization” OR protocol OR recommendation* OR “reimbursement” OR “reminder system” OR “unnecessary prescribing”) AND PUBYEAR > 2012 AND PUBYEAR < 2025 AND NOT INDEX ( medline ) AND NOT ( PMID ( 0* OR 1* OR 2* OR 3* OR 4* OR 5* OR 6* OR 7* OR 8* OR 9* ) ) AND NOT INDEX ( embase ) AND ( LIMIT-TO ( SRCTYPE,“j” ) ) AND ( LIMIT-TO ( DOCTYPE,“ar” ) ) AND ( LIMIT-TO ( LANGUAGE,“English” ) )
2 | SEARCH STRATEGY; AND NOT INDEX ( medline ) AND NOT ( PMID ( 0* OR 1* OR 2* OR 3* OR 4* OR 5* OR 6* OR 7* OR 8* OR 9* ) ) AND NOT INDEX ( embase ); CITATION; Scopus NOT Medline/PubMed NOT Embase - Scopus. In: CADTH Search Filters Database. Ottawa: CADTH; 2024: https://searchfilters.cadth.ca/link/97. Accessed 2024-9-05
3 | KEY = A combined field that searches the AUTHKEY, INDEXTERMS, TRADENAME, and CHEMNAME fields.
4 | TITLE-ABS-KEY-AUTH = A combined field that searches abstracts, document titles, keywords, and author names.
| Total | 2,207