# ABBREVIATIONS TABLE

Abbreviation: Definition
ARR: Absolute risk reduction
ASP: Antimicrobial stewardship programs
ASTF: VA National Antimicrobial Stewardship Taskforce
CDC: Center for Disease Control and Prevention
CDSS: Clinical decision support system
COPD: Chronic obstructive pulmonary disease
CRP: C-reactive protein
DAISY: DistillerSR Artificial Intelligence System
ED: Emergency department
EHR: Electronic health record
ePNA: Electronic pneumonia clinical decision support tool
ER: Emergency room
ESBL: Extended spectrum beta lactamase
FDA: US Food and Drug Administration
GPC: General practice cooperatives
ICD-10: International Classification of Disease, 10th Revision
iCPR: Integrated clinical predication rules
IDSA: Infectious Disease Society of America
IRR: Incidence rate ratio
KQ: Key question
OECD: Organisation for Economic Co-operations and Development
OP: Operational partners
OR: Odds ratio
P4P: Pay for performance
PI: Prediction interval
RCT: Randomized controlled trial
RE-AIM: Reach, Effectiveness, Adoption, Implementation, and Maintenance
ROB: Risk of bias
RR: Risk ratio
RTI: Respiratory tract infection
SSTI: Skin and soft tissue infections
TEP: Technical expert panel
UC: Urgent care
UTI: Urinary tract infection
VA: Veterans Affairs
VHA: Veteran Health Administration