# Supplementary Materials

- Evidence Map_Detailed Character (XLSX)
- Prioritized Studies_Detailed Ch (XLSX)
- Intervention Characteristics (XLSX)
- Comparator Characteristics (XLSX)
- All Outcome Data (XLSX)
- Overall antimicrobial use (XLSX)
- Inappropriate prescribing (XLSX)
- Patient_ Treatment outcomes (XLSX)
- Patient Healthcare utilization (XLSX)
- Microbial resistance (XLSX)
- Sustainability in Prescribing (XLSX)
- Staff satisfaction (XLSX)
- Other barriers & facilitators (XLSX)
- Implementation costs (XLSX)
- Maintenance costs (XLSX)
- Reach_ prescribers, facilities (XLSX)
- Reach_ patients, community (XLSX)
- Excluded Studies (XLSX)
- Risk of Bias Assessments - RCT (XLSX)
- Risk of Bias Assessments - NRCT (XLSX)
- Underway Studies (XLSX)
- Supplementary Search (XLSX)
- Peer Review Feedback (XLSX)

## VA Related Documents

Supplementary Materials (XLSX)