# REFERENCES

1 National Center for Chronic Disease Prevention and Health Promotion. About the center. https://www.cdc.gov/chronicdisease/center/index.htm
2 Keys A AC, Blackburn H, Van Buchem FSP, Buzina R, Djordjević BS, Dontas AS, Fidanza F, Karvonen MJ, Kimura N, Lekos D, Monti M, Puddu V, Taylor HL. Epidemiological studies related to coronary heart disease: Characteristics of men aged 40–59 in seven countries. Acta Med Scand. 1966;
3 Select Committee on Nutrition and Human Needs. Dietary Goals for the United States. 1977. https://books.google.com/books?id=F5syAAAAMAAJ&printsec=frontcover&source=gbs_ge_summary_r&cad=0#v=onepage&q&f=false
4 National Academies of Sciences, Engineering, and Medicine. Guiding Principles for Developing Dietary Reference Intakes Based on Chronic Disease. 2017.
5 Oxford English Dictionary. Inflammation. https://www.oed.com/search/dictionary/?scope=Entries&q=inflammation
6 Furman D, Campisi J, Verdin E, Chronic inflammation in the etiology of disease across the life span. Nat Med. Dec 2019;25(12):1822–1832. doi:10.1038/s41591-019-0675-0 31806905
7 Mukherjee MS, Han CY, Sukumaran S, Delaney CL, Miller MD. Effect of anti-inflammatory diets on inflammation markers in adult human populations: a systematic review of randomized controlled trials. Nutr Rev. Dec 6 2022;81(1):55–74. doi:10.1093/nutrit/nuac045 35831971
8 Conlin PR. The dietary approaches to stop hypertension (DASH) clinical trial: implications for lifestyle modifications in the treatment of hypertensive patients. Cardiol Rev. Sep-Oct 1999;7(5):284–8. doi:10.1097/00045415-199909000-00013 11208239
9 Fidanza F. The Mediterranean Italian diet: keys to contemporary thinking. Proc Nutr Soc. Dec 1991;50(3):519–26. doi:10.1079/pns19910065 1809960
10 Rumawas ME, Dwyer JT, McKeown NM, Meigs JB, Rogers G, Jacques PF. The development of the Mediterranean-style dietary pattern score and its application to the American diet in the Framingham Offspring Cohort. J Nutr. Jun 2009;139(6):1150–6. doi:10.3945/jn.108.103424 19357215
11 U.S. Department of Agriculture and U.S. Department of Health and Human Services. Dietary Guidelines for Americans. 2010.
12 Hebert JR, Shivappa N, Wirth MD, Hussey JR, Hurley TG. Perspective: The Dietary Inflammatory Index (DII)-Lessons Learned, Improvements Made, and Future Directions. Adv Nutr. Mar 1 2019;10(2):185–195. doi:10.1093/advances/nmy071 30615051
13 U.S. Department of Health and Human Services and U.S. Department of Agriculture. 2015–2020 Dietary Guidelines for Americans. https://health.gov/our-work/food-nutrition/previous-dietary-guidelines/2015
14 Boushey C AJ, Bazzano L, Dietary Patterns and All-Cause Mortality: A Systematic Review. 2020. https://www.ncbi.nlm.nih.gov/books/NBK578477/
15 Lichtenstein AH, Appel LJ, Vadiveloo M, 2021 Dietary Guidance to Improve Cardiovascular Health: A Scientific Statement From the American Heart Association. Circulation. Dec 7 2021;144(23):e472–e487. doi:10.1161/CIR.0000000000001031 34724806
16 Kokubo Y, Iwashima Y. Higher blood pressure as a risk factor for diseases other than stroke and ischemic heart disease. Hypertension. Aug 2015;66(2):254–9. doi:10.1161/HYPERTENSIONAHA.115.03480 26077565
17 American Heart Association. What is the Mediterranean Diet? ToCite. https://www.heart.org/en/healthy-living/healthy-eating/eat-smart/nutrition-basics/mediterranean-diet#:~:text=Yes.,vegetable%20oils%20and%20nuts%3B%20and
18 The GRADE Working Group. Grading of recommendations assessment, development and evaluation (GRADE). https://www.gradeworkinggroup.org/
19 AHRQ. Evidence-based Practice Center. https://www.ahrq.gov/research/findings/evidence-based-reports/index.html
20 Schwingshackl L, Knuppel S, Schwedhelm C, Perspective: NutriGrade: A Scoring System to Assess and Judge the Meta-Evidence of Randomized Controlled Trials and Cohort Studies in Nutrition Research. Adv Nutr. Nov 2016;7(6):994–1004. doi:10.3945/an.116.013052 28140319
21 Ali Mohsenpour M, Fallah-Moshkani R, Ghiasvand R, Adherence to Dietary Approaches to Stop Hypertension (DASH)-Style Diet and the Risk of Cancer: A Systematic Review and Meta-Analysis of Cohort Studies. Journal of the American College of Nutrition. 2019;38(6):513–525. Keyword search. doi:10.1080/07315724.2018.1554460 31140934
22 Bloomfield HE, Kane R, Koeller E, Greer N, MacDonald R, Wilt T. Benefits and Harms of the Mediterranean Diet Compared to Other Diets. 2015;Keyword search.
23 Bloomfield HE, Koeller E, Greer N, MacDonald R, Kane R, Wilt TJ. Effects on Health Outcomes of a Mediterranean Diet With No Restriction on Fat Intake: A Systematic Review and Meta-analysis. Annals of internal medicine. 2016;165(7):491–500. Keyword search.27428849
24 Buzzetti E, Linden A, Best LM, Lifestyle modifications for nonalcohol-related fatty liver disease: a network meta-analysis. The Cochrane database of systematic reviews. 2021;6:CD013156. doi:10.1002/14651858.CD013156.pub2
25 Diao H, Yan F, He Q, Association between Dietary Inflammatory Index and Sarcopenia: A Meta-Analysis. Nutrients. 2023;15(1):219. Keyword search. doi:10.3390/nu15010219 36615879
26 Filippou CD, Tsioufis CP, Thomopoulos CG, Dietary Approaches to Stop Hypertension (DASH) Diet and Blood Pressure Reduction in Adults with and without Hypertension: A Systematic Review and Meta-Analysis of Randomized Controlled Trials. Advances in nutrition (Bethesda, Md). 2020;11(5):1150–1160. Keyword search. doi:10.1093/advances/nmaa041 32330233
27 Filippou CD, Thomopoulos CG, Kouremeti MM, Mediterranean diet and blood pressure reduction in adults with and without hypertension: A systematic review and meta-analysis of randomized controlled trials. Clinical nutrition (Edinburgh, Scotland). 2021;40(5):3191–3200. Keyword search. doi:10.1016/j.clnu.2021.01.030 33581952
28 Gibbs J, Gaskin E, Ji C, Miller MA, Cappuccio FP. The effect of plant-based dietary patterns on blood pressure: a systematic review and meta-analysis of controlled intervention trials. Journal of hypertension. 2021;39(1):23–37. Keyword search. doi:10.1097/HJH.0000000000002604 33275398
29 Guo Z, Hong Y, Cheng Y. Dietary inflammatory index and pancreatic cancer risk: a systematic review and dose-response meta-analysis. Public health nutrition. 2021;24(18):6427–6435. Keyword search. doi:10.1017/S1368980021001579 33843543
30 Jabri A, Kumar A, Verghese E, Meta-analysis of effect of vegetarian diet on ischemic heart disease and all-cause mortality. American journal of preventive cardiology. 2021;7:100182. Keyword search. doi:10.1016/j.ajpc.2021.100182 34611632
31 Jafari S, Hezaveh E, Jalilpiran Y, Plant-based diets and risk of disease mortality: a systematic review and meta-analysis of cohort studies. Critical reviews in food science and nutrition. 2022;62(28):7760–7772. Keyword search. doi:10.1080/10408398.2021.1918628 33951994
32 Lee KW, Loh HC, Ching SM, Devaraj NK, Hoo FK. Effects of Vegetarian Diets on Blood Pressure Lowering: A Systematic Review with Meta-Analysis and Trial Sequential Analysis. Nutrients. 2020;12(6)Keyword search. doi:10.3390/nu12061604
33 Limketkai BN, Iheozor-Ejiofor Z, Gjuladin-Hellon T, Dietary interventions for induction and maintenance of remission in inflammatory bowel disease. The Cochrane database of systematic reviews. 2019;2:CD012839. Keyword search. doi:10.1002/14651858.CD012839.pub2 30736095
34 Limketkai BN, Godoy-Brewer G, Parian AM, Dietary Interventions for the Treatment of Inflammatory Bowel Diseases: An Updated Systematic Review and Meta-analysis. Clinical gastroenterology and hepatology : the official clinical practice journal of the American Gastroenterological Association. 2022;Keyword search. doi:10.1016/j.cgh.2022.11.026
35 Moazzen S, van der Sloot KWJ, Vonk RJ, de Bock GH, Alizadeh BZ. Diet Quality and Upper Gastrointestinal Cancers Risk: A Meta-Analysis and Critical Assessment of Evidence Quality. Nutrients. 2020;12(6)doi:10.3390/nu12061863
36 Moazzen S, van der Sloot KWJ, Bock GHd, Alizadeh BZ. Systematic review and meta-analysis of diet quality and colorectal cancer risk: is the evidence of sufficient quality to develop recommendations? Critical reviews in food science and nutrition. 2021;61(16):2773–2782. doi:10.1080/10408398.2020.1786353 32613845
37 Morze J, Danielewicz A, Hoffmann G, Schwingshackl L. Diet Quality as Assessed by the Healthy Eating Index, Alternate Healthy Eating Index, Dietary Approaches to Stop Hypertension Score, and Health Outcomes: A Second Update of a Systematic Review and Meta-Analysis of Cohort Studies. Journal of the Academy of Nutrition and Dietetics. 2020;120(12):1998–2031.e15. doi:10.1016/j.jand.2020.08.076 33067162
38 Morze J, Danielewicz A, Przybylowicz K, Zeng H, Hoffmann G, Schwingshackl L. An updated systematic review and meta-analysis on adherence to mediterranean diet and risk of cancer. European journal of nutrition. 2021;60(3):1561–1586. Keyword search. doi:10.1007/s00394-020-02346-6 32770356
39 Nelson J, Sjoblom H, Gjertsson I, Ulven SM, Lindqvist HM, Barebring L. Do Interventions with Diet or Dietary Supplements Reduce the Disease Activity Score in Rheumatoid Arthritis? A Systematic Review of Randomized Controlled Trials. Nutrients. 2020;12(10)doi:10.3390/nu12102991
40 Nowson CA, Service C, Appleton J, Grieger JA. The Impact of Dietary Factors on Indices of Chronic Disease in Older People: A Systematic Review. The journal of nutrition, health & aging. 2018;22(2):282–296. doi:10.1007/s12603-017-0920-5
41 Poursalehi D, Lotfi K, Saneei P. Adherence to the Mediterranean diet and risk of frailty and pre-frailty in elderly adults: A systematic review and dose-response meta-analysis with GRADE assessment. Ageing research reviews. 2023;87:101903. Keyword search. doi:10.1016/j.arr.2023.101903 36871780
42 Quirk SE, Williams LJ, O'Neil A, The association between diet quality, dietary patterns and depression in adults: a systematic review. BMC psychiatry. 2013;13:175. doi:10.1186/1471-244X-13-175 23802679
43 Schonenberger KA, Schupfer A- C, Gloy VL, Effect of Anti-Inflammatory Diets on Pain in Rheumatoid Arthritis: A Systematic Review and Meta-Analysis. Nutrients. 2021;13(12)Keyword search. doi:10.3390/nu13124221
44 Schwingshackl L, Chaimani A, Schwedhelm C, Comparative effects of different dietary approaches on blood pressure in hypertensive and pre-hypertensive patients: A systematic review and network meta-analysis. Critical reviews in food science and nutrition. 2019;59(16):2674–2687. doi:10.1080/10408398.2018.1463967 29718689
45 Soltani S, Jayedi A, Shab-Bidar S, Becerra-Tomas N, Salas-Salvado J. Adherence to the Mediterranean Diet in Relation to All-Cause Mortality: A Systematic Review and Dose-Response Meta-Analysis of Prospective Cohort Studies. Advances in nutrition (Bethesda, Md). 2019;10(6):1029–1039. Keyword search. doi:10.1093/advances/nmz041 31111871
46 Soltani S, Arablou T, Jayedi A, Salehi-Abargouei A. Adherence to the dietary approaches to stop hypertension (DASH) diet in relation to all-cause and cause-specific mortality: a systematic review and dose-response meta-analysis of prospective cohort studies. Nutrition journal. 2020;19(1):37. Keyword search. doi:10.1186/s12937-020-00554-8 32321528
47 Theodoridis X, Chourdakis M, Chrysoula L, Adherence to the DASH Diet and Risk of Hypertension: A Systematic Review and Meta-Analysis. Nutrients. 2023;15(14):3261. Keyword search. doi:10.3390/nu15143261 37513679
48 Zheng J, Zhao L, Dong J, The role of dietary factors in nonalcoholic fatty liver disease to hepatocellular carcinoma progression: A systematic review. Clinical nutrition (Edinburgh, Scotland). 2022;41(10):2295–2307. doi:10.1016/j.clnu.2022.08.018 36096063
49 Schroder H, Fito M, Estruch R, A short screener is valid for assessing Mediterranean diet adherence among older Spanish men and women. J Nutr. Jun 2011;141(6):1140–5. doi:10.3945/jn.110.135566 21508208
50 WHO Clinical Consortium on Healthy Ageing. Topic focus: frailty and intrinsic capacity. 2017. Report of consortium meeting 1–2 December 2016 in Geneva, Switzerland. https://iris.who.int/bitstream/handle/10665/272437/WHO-FWC-ALC-17.2-eng.pdf?sequence=1