# ACKNOWLEDGMENTS

The authors are grateful to Kathryn Vela for literature searching, Zhaoping Li for content expertise, external peer reviewers, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Tessa Johnson, MS, RDN, IFNCP, RYT
  Clinical Dietitian; National Education Champion
  Nutrition and Food Service Clinical Nutrition Committee, Integrative and Functional Nutrition
  Workgroup
  Office of Patient Centered Care and Cultural Transformation, Eating for Whole Health
- Katherine Dignan, MS, RD, LD, CDCES
  Clinical Dietitian
  Nutrition and Food Service Clinical Nutrition Committee, Integrative and Functional Nutrition
  Workgroup
- Kwynn Mason, MPH, RDN, LDN, CLS, IFNCP
  Clinical Dietitian
  Nutrition and Food Service Clinical Nutrition Committee, Integrative and Functional Nutrition
  Workgroup
- Glory Rodriguez-Gomez, MS, RDN, CDCES, LD, IFNCP
  Employee Whole Health Coordinator
  Nutrition and Food Service Clinical Nutrition Committee, Integrative and Functional Nutrition
  Workgroup

## Technical Expert Panel

To ensure robust, scientifically relevant work, the technical expert panel (TEP) guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members included:

- Shari Pollack, MPH, RDN, LDN
  Employee Whole Health Coordinator
  Jesse Brown VA Medical Center
- Julie Obbagy, PhD, RD
  Nutritionist
  Center for Nutrition and Promotion, Food and Nutrition Service, U.S. Department of Agriculture
- Wendy Kohatsu, MD, ABOIM
  Techworks Consultant
  VA Office of Patient Centered Care and Cultural Transformation