# DISCUSSION

A large number of chronic health conditions have been associated with inflammation or inflammatory states, with varying amounts of evidence and plausible proposed mechanisms supporting those associations. The literature assessing the benefits of various diets that have been categorized as being potentially anti-inflammatory for these health conditions (or the association between adoption of such diets and risk for the conditions) is likewise vast.

For the purpose of producing an evidence map that focused on conditions of interest to the sponsor, for which no recent reviews of reviews (or umbrella reviews) were conducted, and that aimed to identify associations with at least moderate supporting evidence, we limited this review to systematic reviews that:

- Considered the MD (eating pattern), DASH diet, anti-inflammatory diet (as assessed by the DII), or vegan/vegetarian/plant-based diets.
- Assessed outcomes related to autoimmune disorders, blood pressure or hypertension, cancer, cognitive function, frailty, and liver diseases.
- Assessed the strength of the body of evidence underlying their conclusions using the GRADE method or a similar approach.

It is important to note that despite the variety of methods used to assess adherence to a Mediterranean dietary pattern (reflecting the many culture-specific variations) and the apparent differences among the eating patterns we considered in this report (especially the Mediterranean and DASH diets), these dietary patterns actually share many aspects in common. These include an emphasis on a variety of vegetables, legumes, fruits, (less processed) grains, nuts, (less-saturated) vegetable (over animal fats), and minimal intakes of red meat and full-fat dairy products. The nutrient profiles that the DII aims to capture also reflect those of the MD and DASH diets.

Among 18 reviews that met the inclusion criteria for this review, only 5 drew conclusions that the authors of those reviews judged as being supported by high-certainty evidence. Two of these conclusions were that the DASH diet, a diet that was originally developed as an approach to preventing or controlling hypertension, was shown to have a beneficial effect on blood pressure and to be associated with lower risk for all-cause or cancer mortality (see Table 8).

Two conclusions with high certainty of evidence, both from the same study, addressed the impact of the MD on—or the association of the diet with—risk for frailty. Both showed beneficial effects or associations.

Table 8 Conclusions with High Strengths of Evidence and Numbers and Types of Studies Supporting Them

Author, Year | Clinical Topic Area Primary Studies | Abridged Conclusion Text from Systematic Review
Gibbs, 2021 ^28^ | BP; 5 RCT | “Consumption of the lacto-ovo vegetarian diet was associated with statistically significant reductions in DBP compared with the consumption of comparator diets.”
Soltani, 2020 ^46^ | All-cause mortality; 13 Observational studies | “5-point increment in the adherence to the DASH diet could significantly lower the all-causes by 5%.”
Gibbs, 2021 ^28^ | BP; 11 RCT | “Consumption of the DASH diet was associated with statistically significant reductions in SBP and DBP compared with the consumption of comparator diets.”
Schwingshackl, 2019 ^44^ | BP; 3 RCT | “The present network meta-analysis suggests that the DASH dietary approach might be the most effective dietary measure to reduce BP among hypertensive and pre-hypertensive patients based on high quality evidence.”
Soltani, 2020 ^46^ | Cancer mortality – general; 10 Observational studies | “5-point increment in the adherence to the DASH diet could significantly lower the cancer mortality by 3%.”
Poursalehi, 2023 ^41^ | Risk of frailty; 7 Observational studies | “Better adherence to MD is associated with a decreased risk of frailty and pre-frailty among older adults.”
Poursalehi, 2023 ^41^ | Risk of frailty; 12 Observational studies | “Better adherence to MD is associated with a decreased risk of frailty and pre-frailty among older adults.”

Abbreviations. BP=blood pressure; DASH=Dietary Approaches to Stop Hypertension; DBP=diastolic blood pressure; MD=Mediterranean diet; SBP=systolic blood pressure.

Table 9 Conclusions with Moderate Strengths of Evidence and Numbers and Types of Studies Supporting Them

Author, Year | Clinical Topic Area | Abridged Conclusion Text from Systematic Review
Morze, 2020 ^37^ | All-cause mortality; 15 Observational studies | “Highest vs lowest category of diet quality (assessed by DASH score) were inversely associated with risk of all-cause mortality.”
Filippou, 2021 ^27^ | BP; 35 RCT | “The adoption of the MD was accompanied by a relatively small, but yet significant BP reduction, while higher baseline SBP levels and longer follow-up duration enhanced the BP-lowering effect of the intervention.”
Filippou, 2020 ^26^ | BP; 30 RCT | “Compared with a control diet, the DASH diet reduced both SBP and DBP, and hypertension status did not modify the effect on BP reduction.”
Gibbs, 2021 ^28^ | BP; 8 RCT | “Consumption of the MD was associated with statistically significant reduction in SBP and non-statistically significant reduction in DBP compared with the consumption of comparator diets.”
Gibbs, 2021 ^28^ | BP; 5 RCT | “Consumption of the lacto-ovo vegetarian diet was associated with statistically significant reductions in SBP and DBP compared with the consumption of comparator diets.”
Morze, 2021 ^38^ | Cancer mortality – general; 19 Mixed studies | “The MD was related to lower risk of cancer mortality in the general population.”
Ali Mohsenpour, 2019 ^21^ | Cancer mortality – general; 9 Observational studies | “Highest versus lowest adherence to a DASH-style diet significantly decreased the risk of mortality from all cancer types.”
Morze, 2020 ^37^ | Cancer risk – general and cancer mortality – general; 25 Observational studies | “Highest vs lowest category of diet quality (assessed by DASH score) were inversely associated with risk of cancer mortality or incidence.”
Nowson, 2018 ^40^ | Cognitive function; 18 Mixed studies | “A diet with MD characteristics is associated with reduced cognitive decline.”

Abbreviations. BP=blood pressure; DASH=Dietary Approaches to Stop Hypertension; DBP=diastolic blood pressure; MD=Mediterranean diet; SBP=systolic blood pressure.

Moderate certainty of evidence supported 18 conclusions regarding the diets investigated and associated health outcomes: 8 conclusions about the MD, 6 conclusions about the DASH Diet, 3 conclusions regarding lower DII scores, and 1 conclusion regarding effects of vegetarian/plant-based diets.

SRs of RCTs examining the impact of the MD, DASH diet, and lacto-ovo vegetarian diets showed that a moderate certainty of evidence supported a role of these diets in reducing blood pressure. SRs of observational studies found associations of the MD, DASH diet, and lower DII scores with reductions in various cancer risk outcomes: for example, higher adherence to the MD and the DASH diet and lower DII scores were associated with lower risks for CRC and HCC and lower cancer-associated mortality. Moderate certainty of evidence supported associations of both the MD and the DASH diet and lower DII scores with lower risks for cirrhosis and NAFLD. Finally, a moderate certainty of evidence supported an association of the MD with reduced risk for cognitive decline and an association of lower DII scores with reduced risk for frailty.

Limitations

This evidence map had several limitations.

The first, common to all SRs, is that we might not have identified all the potentially eligible evidence. If a systematic review was published in a journal not indexed in any of the databases we searched, then we would have missed it. An extension to this limitation is that the included systematic reviews may themselves have missed some original research studies eligible for their review. An additional factor that limited inclusion of studies on some conditions of interest (such as depression, fibromyalgia, and myalgic encephalomyelitis/chronic fatigue syndrome) is that we included only systematic reviews that formally assessed the strength of the evidence; however, this stipulation can only have served to increase the quality of the reviews we included.

The second limitation, which pertains to evidence maps, is that we did not independently evaluate the source evidence; in other words, we took the conclusions of the authors of the systematic review at face value. That is the nature of an evidence map. As in all evidence-based products, and particularly in one such as this covering a large and complex evidence base, it is possible there are errors of data extraction and compilation. We used dual review to minimize the chance of such errors, but if we are notified of errors, we will correct them.

A third limitation, one that is common to all research on the role of nutrition in chronic disease prevention/etiology and management, is that most of the original studies, with the exception of the studies on BP, are observational, so the chance of identifiable and unidentifiable confounders is higher, and the certainty of evidence is usually not high. However, because we chose to include only reviews that graded the certainty of evidence supporting their conclusions, the quality of the original studies has at least been taken into account. Unfortunately, outcome measures for RCTs are likely to be relatively short term and are more likely to be biomarkers or other intermediate outcomes of unclear predictive value than longer-term clinical outcomes (except for studies on BP and hypertension, which are key risk factors for a variety of diseases), but well-designed observational studies of dietary patterns can yield important insights about long-term health and chronic disease outcomes.

A fourth limitation of this review, which is actually a limitation of the SRs and the original studies themselves, is the way that interventions or exposures are defined. For example, studies of the MD employ at least 9 different indices to measure adherence to the diet. SRs on the associations of MD adherence with health outcomes typically disregarded the indices used by individual studies. Although we found no formal comparisons among these indices, and simply reported the conclusions of the SRs, we did ascertain that the various indices were capturing important aspects of the MD. Assessment of the association of adherence to an anti-inflammatory diet usually relied on use of the DII, rather than trials of specific dietary guidance or meal provision. But more concerning is that the data used to calculate these scores are self-reported food frequency or dietary recall data, whose limitations are well recognized.

A final limitation, which is actually a challenge to the field, is the lack of scientific consensus on what constitutes an anti-inflammatory eating pattern. The criteria used to define an anti-inflammatory eating pattern is not consistent across studies, and in fact, the criteria used to define specific diets and diet indices, such as the Mediterranean diet (for which there are at least 5 indices), are not consistent. Although this makes it difficult to compare the effects of one diet against another, the DASH diet and the many variations of the Mediterranean diet have much in common. Both promote increased consumption of fruits, vegetables, whole grains, legumes, and nuts and seeds, although the Mediterranean Diet promotes additional foods or ingredients with anti-inflammatory properties such as olive oil, fish, and herbs and spices. Studies that focus specifically on an anti-inflammatory diet, such as those that use the DII, are still too few in number and too limited in design to enable more far-reaching conclusions to be drawn.

## FUTURE RESEARCH

Definitively determining the impact of diets that might have anti-inflammatory properties on the risk of developing chronic diseases depends on first identifying several missing pieces in the biological plausibility chain. Most importantly, intermediate outcomes such as biomarkers that have consistent, significant associations—positive or negative—with disease risk must be identified and ideally, some chain of causality must be established. Inflammation is a natural process that serves vital physiological roles: Thus, the idea that a dietary pattern that non-selectively suppresses inflammation might have health benefits needs extensive clarification. Then it will be necessary to determine whether certain combinations of foods or nutrients or certain overall dietary patterns or the avoidance of certain foods or patterns are responsible for the observed outcomes and whether the outcomes are affected by factors such as genetics and other lifestyle characteristics.

## CONCLUSIONS

Moderate or high certainty evidence linking diets with anti-inflammatory characteristics to chronic disease prevention or management outcomes is strong for some conditions but remains relatively sparse for others. Nevertheless, the evidence suggests that adherence to diets such as DASH and Mediterranean-type eating patterns might have beneficial associations with a multitude of health risks. Moreover, adverse events or harms associated with these diets are essentially non-existent.