# EVIDENCE MAPS

We constructed 4 evidence maps, one each for the following diets: MD, DASH diet, DII, and vegetarian/plant-based diet. Two additional diets that did not have any moderate or high certainty of evidence conclusions are included in the final section. In these figures, each shape represents a single conclusion from a single systematic review: Triangles are reviews of RCTs only, squares are reviews of only observational studies, and diamonds represent reviews of both RCTs and observational studies.

## MEDITERRANEAN DIET

The main components of the MD as originally studied were described in the introduction and were based on dietary patterns found in Italy and Greece. Because dietary scores based on the original dietary patterns might not be appropriate for non-Mediterranean populations, the original assessment metrics have been adapted to create numerous spinoff definitions and measures of adherence or exposure. These include the Mediterranean Diet Score (MDS); Mediterranean-style Dietary Pattern Score (MSDPS), which is based on the original Mediterranean Dietary Pyramid food groups but also accounts for foods not included in the Pyramid; the Alternate Mediterranean Diet (AMED), which does not include legumes as a separate food group; or the 14-item Mediterranean Diet Adherence Screener (MEDAS).^10,49^ Typically, these tools are either used to directly assess intakes of various food groups or they are applied to analyze dietary recall or other food frequency questionnaire data. The results are then expressed as servings from specific food groups or they are translated to some subset of nutrients provided by those food intakes. Each of the Mediterranean diet assessment tools also varies slightly in the panel of nutrients included (eg, including or excluding alcohol).

Thirteen systematic reviews that met inclusion criteria attempted to assess the effects of a MD on—or association of the MD with—health outcomes of interest (see Figure 1). Seven of the systematic reviews reported conclusions with moderate or high SoE.^27,28,38–41,48^ Table 2 reports the conclusions, in order of condition, as described in the reviews.

RCTs included in the reviews had 1 of 2 designs: some provided participants with all their meals and snacks, and some provided menus for participants to follow. Both the RCTs and the observational studies included in each systematic review used various measures to assess adherence and intake, as described above.

### Blood Pressure

Two reviews assessed the effects of the MD diet on BP in RCTs.^27,28^ A 2021 systematic review and meta-analysis that pooled 35 RCTs reported that compared with maintaining usual diet, adopting a MD resulted in a small but significant decrease in both systolic blood pressure (SBP) and diastolic blood pressure (DBP) in both those with hypertension and those with normal BP. But when the MD was compared with adopting other active dietary interventions, there was no difference in blood pressure. This conclusion had a moderate certainty of evidence .^27^ A second 2021 systematic review and meta-analysis identified eight RCTs assessing the effects of the MD on BP, 6 of which were included in the larger review; this review reported that the MD reduces both SBP and DBP (but did not distinguish the effects of the MD compared with standard diet from the effects of the MD compared with other active dietary interventions).^28^ This conclusion also had a moderate certainty of evidence.

### Frailty

The World Health Organization defines frailty as “a clinically recognizable state in which the ability of older people to cope with everyday or acute stressors is compromised by an increased vulnerability brought by age-associated declines in physiological reserve and function across multiple organ systems.”^50^

One review conducted a dose-response meta-analysis on the association between MD adherence (2-point increases in MDS) and the risk for frailty in 12 cohort studies and 7 cross-sectional studies.^41^ The authors reported that higher MDS was associated with a decreased risk for frailty and pre-frailty among older adults in both cohort and cross-sectional studies: Both conclusions (from each of the two sets of studies) reached a high certainty of evidence.

### Cancer and All-Cause Mortality Outcomes

Five reviews assessed the association between MD and various outcomes related to cancer risk or incidence, cancer mortality, or all-cause mortality.

One review assessed the association between various anti-inflammatory diets and HCC, incident NAFLD, and cirrhosis and found an inverse association between adherence to MD and incidence of HCC (4 case control and 3 cohort studies), and incident NAFLD and cirrhosis (7 cohort studies).^48^ These conclusions had a moderate certainty of evidence.

A second systematic review and meta-analysis, which updated an earlier review by the same research group, assessed the association between adherence to the MD and risks for cancer mortality, site-specific cancer in the general population, all-cause mortality, and cancer mortality, as well as cancer reoccurrence among cancer survivors.^37,38^ The review included 117 studies and used Nutrigrade to assess certainty of evidence. Assessment of 1 RCT and 18 cohort studies showed a decrease in risk for mortality from all cancers with higher adherence to the MD; this conclusion had a moderate certainty of evidence. Analysis of 34 observational studies showed moderate certainty of evidence for a reduction in risk for CRC with higher adherence to the MD.

### Cognition

One review assessed the association of MD with the risk for cognitive decline in older adults.^40^ This review included 18 studies—1 RCT (the PREDIMED trial, 13 cohort studies, and 3 cross-sectional studies. Using an Australian method (also called GRADE), the reviewers assessed the certainty of evidence for a positive association between MD index scores and various measures of cognitive function as good (GRADE B or moderate).

### Rheumatoid Arthritis

One review assessed the impact of following a MD (among various diets, intakes of specific foods, and uses of dietary supplements) on Disease Activity Score in 28 joints (DAS28).^39^ The review identified 1 RCT that assessed the impact of a MD intervention and one that assessed the impact of a Mediterranean-style anti-inflammatory diet intervention. The reviewers assessed the certainty of evidence as moderate for a beneficial effect of the diet on DAS28, although one of the studies did not report an effect size.

The additional 12 conclusions in the evidence map were rated low or very low certainty of evidence and thus did not have sufficient certainty to be discussed here in detail. See Table 2 for details from all MD conclusions.

Figure 1 Evidence Map of Mediterranean Diet

Table 2 Evidence Table of Mediterranean Diet Conclusions

Author, Year | Clinical Topic Area | Certainty of Evidence Primary Studies | Abridged Conclusion Text from Systematic Review
Bloomfield, 2015 ^22^ | All-cause mortality | Low; 3 RCT | “All cause mortality is about the same as the control diet.”
Bloomfield, 2016 ^23^ | All-cause mortality | Low; 2 RCT | “Incidence of all-cause mortality was similar between the Mediterranean-like diet and the control diet groups.”
Soltani, 2019 ^45^ | All-cause mortality | Low; 29 Observational studies | “Each 2-point increment in the adherence to a MD is associated with a 10% reduction in the risk of all-cause mortality.”
Filippou, 2021 ^27^ | BP | Moderate; 35 RCT | “The adoption of the MD was accompanied by a relatively small, but yet significant BP reduction, while higher baseline SBP levels and longer follow-up duration enhanced the BP-lowering effect of the intervention.”
Gibbs, 2021 ^28^ | BP | Moderate; 8 RCT | “Consumption of the MD was associated with statistically significant reduction in SBP and non-statistically significant reduction in DBP compared with the consumption of comparator diets.”
Morze, 2021 ^38^ | Cancer mortality – general | Moderate; 19 Mixed studies | “The MD was related to lower risk of cancer mortality in the general population.”
Bloomfield, 2016 ^23^ | Cancer risk – general | Low; 3 Observational studies | “Three large cohort studies reported highest conformity to a MD was associated with a reduction in total cancer incidence compared with lowest conformity (reference group).”
Bloomfield, 2016 ^23^ | Cognitive function | Low; 17 Mixed studies | “Cognitive functioning [inconsistent/mixed results in observational studies and RCTs].”
Nowson, 2018 ^40^ | Cognitive function | Moderate; 18 Mixed studies | “A diet with MD characteristics is associated with reduced cognitive decline.”
Quirk, 2013 ^42^ | Depressive symptoms | Low; 1 Observational study | “No association between a traditional MD and the likelihood of depressive symptoms.”
Zheng, 2022 ^48^ | NAFLD and cirrhosis | Moderate; 7 Observational studies | “MDS and alternative MD was negatively associated with incident NAFLD and cirrhosis.”
Nelson, 2020 ^39^ | Rheumatoid arthritis | Moderate; 2 RCT | “The MD reduced DAS28 in rheumatoid arthritis.”
Bloomfield, 2016 ^23^ | Risk of breast cancer | Low; 14 Mixed studies | “One RCT reported breast cancer incidence was lower in the combined MD groups compared to control; 13 cohort studies found breast cancer incidence was similar between the highest and lowest conformity groups.”
Bloomfield, 2016 ^23^ | Risk of CRC | Low; 9 Observational studies | “Highest conformity to a MD was associated with a reduction in CRC incidence compared with the lowest conformity.”
Moazzen, 2021 ^36^ | Risk of CRC | Very low; 16 Mixed studies | “High diet quality quantified by the MDS was significantly associated with a lower risk of CRC.”
Morze, 2021 ^38^ | Risk of CRC | Moderate; 34 Observational studies | “The MD was related to lower risk of CRC.”
Nowson, 2018 ^40^ | Risk of frailty | Low; 3 Observational studies | “Following a diet with Mediterranean dietary characteristics may be associated with decreased likelihood of frailty.”
Poursalehi, 2023 ^41^ | Risk of frailty | High; 7 Observational studies | “Better adherence to MD is associated with a decreased risk of frailty and pre-frailty among older adults.”
Poursalehi, 2023 ^41^ | Risk of frailty | High; 12 Observational studies | “Better adherence to MD is associated with a decreased risk of frailty and pre-frailty among older adults.”
Zheng, 2022 ^48^ | Risk of liver cancer | Moderate; 5 Observational studies | “MDS and alternative MD was negatively associated with HCC.”
Moazzen, 2020 ^35^ | Risk of UGI cancer | Very low; 11 Observational studies | “High scores in the MDS had a significant protective effect on the risk of upper gastrointestinal (UGI) cancer.”
Buzzetti, 2021 ^24^ | Various liver disease outcomes | Very low; 1 RCT | “Associations were not estimable because ‘there were no events in either group’ (see table Summary of findings 1. starting on p6).”

Abbreviations. BP=blood pressure; CRC=colorectal cancer; DAS28=Disease Activity Score in 28 joints; DBP=diastolic blood pressure; HCC=hepatocellular carcinoma; NAFLD=nonalchoholic fatty liver disease; MD=Mediterranean diet; MDS=Mediterranean Diet Score; SBP=systolic blood pressure; UGI=upper gastrointestinal.

## DASH DIET

The DASH diet pattern was described in the introduction. Seven of 9 systematic reviews that met inclusion criteria reported moderate or high certainty conclusions linking the DASH diet with beneficial health outcomes (see Figure 2 and Table 3).^21,26,28,37,44,46,48^ Adherence or exposure to the DASH diet was typically measured using the DASH score when reported in observational studies, and assignment to the DASH treatment option was used in RCTs.

### All-Cause Mortality

Two reviews assessed observational studies to examine associations between DASH diet scores and all-cause mortality, with both reaching conclusions that the DASH diet was associated with lower all-cause mortality (with moderate and high certainty of evidence). The first review and meta-analysis (of a variety of dietary indices used in cohort studies) identified 15 DASH score cohort studies and found that the highest DASH scores, when compared to lowest DASH scores, were inversely associated with risk of all-cause mortality (moderate certainty of evidence).^37^ The second review, a systematic review and dose-response meta-analysis of prospective cohort studies on DASH diet and mortality, found 13 prospective cohort studies related to all-cause mortality.^46^ The meta-analysis pooling these studies found that higher adherence to the DASH diet was associated with lower all-cause mortality (high certainty of evidence).

### Blood Pressure

Four systematic reviews addressed the link between the DASH diet and blood pressure. Three of the reviews drew conclusions with high or moderate certainty of evidence.

The first meta-analysis focused exclusively on RCTs of DASH diet and BP, and found that among the 30 RCTs that compared DASH diet with control diets, DASH reduced SBP and DBP in adults with or without hypertension (moderate certainty of evidence).^26^

The second systematic review conducted meta-analyses for multiple diets including DASH and pooled 11 RCTs of DASH diet to reach a high certainty of evidence conclusion that DASH diet was associated with reductions in SBP and DBP when compared with other diets.^28^

The third review related to BP was a network meta-analysis of 67 trials comparing 13 dietary approaches, including 3 DASH diet trials, for both SBP and DBP.^44^ The authors found that of the 13 dietary approaches, the DASH diet was most effective at reducing BP in both hypertensive and pre-hypertensive patients (high certainty of evidence).

### Cancer Outcomes

Seven reviews assessed the evidence regarding a link between the DASH diet and cancer outcomes. Three reviews reported 4 conclusions with moderate to high certainty of evidence. Two of these were described above, as they also reported on all-cause mortality. The remaining 4 reviews reported conclusions with low to very low certainty of evidence.

The first dose-response meta-analysis described above in the all-cause mortality section also included another analysis of 10 prospective cohort studies and found that DASH diet lowered cancer mortality (high certainty of evidence).^46^

The second review described above also concluded that the DASH diet was inversely associated with risk of cancer, with 25 cohort studies included.^37^ Their moderate certainty of evidence conclusion also included an inverse association between DASH diet and cancer incidence.

The third review, also a systematic review and meta-analysis of cohort studies, included 2 conclusions, both relating to DASH diet cancer outcomes.^21^ The first conclusion, based on 9 cohort studies, found that higher adherence to DASH diet decreased cancer mortality, similar to the findings in the other 2 reviews (moderate certainty of evidence). The second conclusion was that adherence to a DASH diet decreased the risk of CRC (moderate certainty of evidence).

### Liver

One review assessed the impact of multiple diets on NAFLD and HCC.^48^ The review reached 1 conclusion, based on 4 observational studies, that the DASH diet was negatively associated with risk of NAFLD and liver cirrhosis (moderate certainty of evidence).

The additional 6 conclusions in the evidence map were rated low or very low certainty of evidence and thus did not have sufficient certainty to be discussed here in detail. See Table 3 for details from all DASH diet conclusions.

Figure 2 Evidence Map of DASH Diet

Table 3 Evidence Table of DASH Conclusions

Author, Year | Clinical Topic Area | Certainty of Evidence Primary Studies | Abridged Conclusion Text from Systematic Review
Morze, 2020 ^37^ | All-cause mortality | Low; 6 Observational studies | “Highest vs lowest category of diet quality (assessed by DASH score) were inversely associated with risk of all-cause mortality among cancer survivors.”
Morze, 2020 ^37^ | All-cause mortality | Moderate; 15 Observational studies | “Highest vs lowest category of diet quality (assessed by DASH score) were inversely associated with risk of all-cause mortality.”
Soltani, 2020 ^46^ | All-cause mortality | High; 13 Observational studies | “5-point increment in the adherence to the DASH diet could significantly lower the all-causes by 5%.”
Filippou, 2020 ^26^ | BP | Moderate; 30 RCT | “Compared with a control diet, the DASH diet reduced both SBP and DBP, and hypertension status did not modify the effect on BP reduction.”
Gibbs, 2021 ^28^ | BP | High; 11 RCT | “Consumption of the DASH diet was associated with statistically significant reductions in SBP and DBP compared with the consumption of comparator diets.”
Schwingshackl, 2019 ^44^ | BP | High; 3 RCT | “The present network meta-analysis suggests that the DASH dietary approach might be the most effective dietary measure to reduce BP among hypertensive and pre-hypertensive patients based on high quality evidence.”
Theodoridis, 2023 ^47^ | BP | Very low; 12 Observational studies | “The findings suggest that high adherence to the DASH diet has a positive effect on reducing hypertension risk compared to low adherence.”
Ali Mohsenpour, 2019 ^21^ | Cancer mortality – general | Moderate; 9 Observational studies | “Highest vs lowest adherence to a DASH-style diet significantly decreased the risk of mortality from all cancer types.”
Morze, 2020 ^37^ | Cancer mortality – general | Low; 6 Observational studies | “Highest vs lowest category of diet quality (assessed by DASH score) were inversely associated with risk of cancer mortality among cancer survivors.”
Soltani, 2020 ^46^ | Cancer mortality – general | High; 10 Observational studies | “5-point increment in the adherence to the DASH diet could significantly lower the cancer mortality by 3%.”
Morze, 2020 ^37^ | Cancer risk – general and cancer mortality – general | Moderate; 25 Observational studies | “Highest vs lowest category of diet quality (assessed by DASH score) were inversely associated with risk of cancer mortality or incidence.”
Zheng, 2022 ^48^ | NAFLD and cirrhosis | Moderate; 4 Observational studies | “DASH diet was negatively associated with incident NAFLD and cirrhosis.”
Morze, 2020 ^37^ | Neurodegenerative disease risk | Low; 7 Observational studies | “Highest vs lowest category of diet quality (assessed by DASH score) were inversely associated with risk of neurodegenerative disease.”
Ali Mohsenpour, 2019 ^21^ | Risk of CRC | Moderate; 4 Observational studies | “Highest vs lowest adherence to a DASH-style diet significantly decreased the risk of CRC.”
Moazzen, 2021 ^36^ | Risk of CRC | Very low; 8 Mixed studies | “High diet quality quantified by the DASH score was significantly associated with a lower risk of CRC.”
Zheng, 2022 ^48^ | Risk of liver cancer | Very low; 3 Observational studies | “DASH diet showed inconsistent association with HCC.”

Abbreviations. BP=blood pressure; CRC=colorectal cancer; DASH=Dietary Approaches to Stop Hypertension; DBP=diastolic blood pressure; HCC=hepatocellular carcinoma; NAFLD=nonalchoholic fatty liver disease; SBP=systolic blood pressure.

## DIETARY INFLAMMATORY INDEX

The Dietary Inflammatory Index was developed to enable the assessment of individual and group food intakes and dietary patterns for their inclusion of some 45 nutrients that have been associated with increased or decreased levels of biomarkers that have been associated with chronic inflammation (inflammatory cytokines) as well as with chronic disease risk (higher scores reflect inclusion of larger amounts of nutrients thought to promote inflammation).^12^ The DII has undergone several modifications to reflect changes in the evidence and has been used to score measures of food intake across more than 10 countries (such as NHANES data for the US).

Five systematic reviews were identified that met inclusion criteria and assessed the association of DII scores on outcomes of interest (Figure 3 and Table 4).

### Cancer Outcomes

Two reviews assessed the association of the DII, or pattern, on cancer—one on liver cancer (HCC) ^48^ and the second review on pancreatic cancer^29^ (see Figure 3). Both reviews relied exclusively on observational data: The liver cancer review reported on 2 case-control studies and 1 cohort study, and the pancreatic cancer review reported on 2 cohort studies and 4 case-control studies. In the latter, the findings on pancreatic cancer were meta-analytically pooled. Both reviews found moderate certainty evidence that diets with a higher DII were associated with increasing progression of chronic liver disease to HCC^48^ or development of pancreatic cancer.^29^

### Frailty

An additional review that also meta-analytically combined observational data concluded that diets with a higher DII were associated with sarcopenia (with moderate certainty evidence), however 9 of the 11 included studies were cross-sectional in design, which precludes drawing conclusions even about association.^25^ Point estimates from the cohort studies did not show any statistically significant association between higher DII and sarcopenia.

The additional 2 conclusions in the evidence map were rated very low certainty of evidence and thus did not have sufficient certainty to be discussed here in detail. See Table 4 for details from all DII diet conclusions.

Figure 3 Evidence Map of Dietary Inflammatory Index

Table 4 Evidence Table of Dietary Inflammatory Index Conclusions

Author, Year | Clinical Topic Area | Certainty of Evidence Primary Studies | Abridged Conclusion Text from Systematic Review
Zheng, 2022 ^48^ | NAFLD, cirrhosis, and liver cancer | Moderate; 3 Observational studies | “DII was positively associated with incident NAFLD, cirrhosis, and HCC.”
Moazzen, 2021 ^36^ | Risk of CRC | Very low; 11 Mixed studies | “High diet quality quantified by the DII was significantly associated with a lower risk of CRC.”
Guo, 2021 ^29^ | Risk of pancreatic cancer | Moderate; 6 Observational studies | “Results suggested that dietary habits with high inflammatory features (high DII score compared to lower score) might increase pancreatic cancer risk.”
Moazzen, 2020 ^35^ | Risk of UGI cancer | Very low; 9 Observational studies | “Low DII scores did indicate statistically significant protection against UGI cancer.”
Diao, 2023 ^25^ | Sarcopenia | Moderate; 11 Observational studies | “The meta-analysis indicated that the DII is associated with sarcopenia. Meanwhile, the result of the dose–response analysis showed that sarcopenia increased by 1.22 times for each 1-point increase in the DII score.”

Abbreviations. CRC=colorectal cancer; DII=Dietary Inflammatory Index; HCC=hepatocellular carcinoma; NAFLD=nonalchoholic fatty liver disease; UGI=upper gastrointestinal.

## EVIDENCE MAP OF VEGETARIAN OR OTHER PLANT-BASED DIET

Three reviews were identified that met inclusion criteria and considered studies of diets labeled as anti-inflammatory. The conclusions reached by these 3 reviews—2 on risk for inflammatory bowel disorder and 1 on chronic pain—were all deemed low or very low certainty of evidence conclusions (Figure 5 and Table 6).

### Blood Pressure

Two reviews of only RCTs concluded that compared to non-vegetarian diets in 5 clinical trials, plant-based dietary patterns were associated with lower SBP (high certainty evidence) and DBP (moderate certainty evidence) (see Figure 4 and Table 5).^28^

The additional 3 conclusions in the evidence map were rated very low certainty of evidence and thus did not have sufficient certainty to be discussed here in detail. See Table 5 for details from all vegetarian or other plant-based diet conclusions.

Figure 4 Evidence Map of Vegetarian/Plant-Based Diet

Table 5 Evidence Table of Vegetarian/Plant-Based Diet Conclusions

Author, Year | Clinical Topic Area | Certainty of Evidence Primary Studies | Abridged Conclusion Text from Systematic Review
Jabri, 2021 ^30^ | All-cause mortality | Very low; 8 Observational studies | “There was no association between vegetarian diet and [all-cause] mortality.”
Jafari, 2022 ^31^ | All-cause mortality and cancer mortality – general | Very low; 12 Observational studies | “A decrease in hazard ratios for all-cause mortality and no association with any cancer mortality.”
Gibbs, 2021 ^28^ | BP | High; 5 RCT | “Consumption of the lacto-ovo vegetarian diet was associated with statistically significant reductions in SBP and DBP compared with the consumption of comparator diets.”
Gibbs, 2021 ^28^ | BP | Moderate; 5 RCT | “Consumption of the lacto-ovo vegetarian diet was associated with statistically significant reductions in SBP and DBP compared with the consumption of comparator diets.”
Lee, 2020 ^32^ | BP | Very low; 15 RCT | “Compared to meat diet, vegetarian dietary pattern significantly reduced SBP and DBP.”

Abbreviations. BP=blood pressure; DBP=diastolic blood pressure; SBP=systolic blood pressure.

## OTHER ANTI-INFLAMMATORY DIETS

A large number of epidemiological studies have linked lower intakes of animal foods (non-lean meat and full-fat dairy products) with lower risks for chronic diseases, including obesity. However, the terms vegetarian diet or plant-based diet have no exact definitions or criteria in terms of the range of contents of animal products or even their overall nutritive values. Even vegan diets (covered in a separate section, below), which completely exclude any animal products and have also been associated with lower chronic disease risks, adhere to no criteria regarding nutrient contents. Thus, reviews of these diets entirely lack standardization of interventions or exposures. For this evidence map review, we identified 4 reviews that met inclusion criteria: 2 that included only RCTs and 2 that included only observational studies.

Figure 5 Evidence Map of Anti-Inflammatory Diet

Table 6 Evidence Table of Anti-Inflammatory Diet Conclusions

Author, Year | Clinical Topic Area | Certainty of Evidence Primary Studies | Abridged Conclusion Text from Systematic Review
Schonenberger, 2021 ^43^ | Rheumatoid arthritis - pain | Very low; 7 RCT | “Our meta-analysis showed a significant improvement in pain in rheumatoid arthritis patients on anti-inflammatory diets compared with ordinary diets.”
Limketkai, 2019 ^33^ | Ulcerative colitis | Very low; 1 RCT | “At 6 months, 36% (5/14) of participants in the Alberta-based anti-inflammatory diet group[’s ulcerative colitis] relapsed compared to 29% (4/14) of participants in the control group.”
Limketkai, 2022 ^34^ | Ulcerative colitis | Very low; 1 RCT | “There was no observed benefit from [an] anti-inflammatory diet... for the maintenance of 26- to 52-week clinical remission, or for quality of life.”

## VEGAN DIET

The 1 conclusion in the evidence map was rated low certainty of evidence and thus does not have sufficient certainty to be discussed here in detail. See Figure 6 and Table 7 for details from this vegan diet conclusion.

Figure 6 Evidence Map of Vegan Diet

Table 7 Evidence Table of Vegan Diet Conclusions

Author, Year | Clinical Topic Area | Certainty of Evidence Primary Studies | Abridged Conclusion Text from Systematic Review
Gibbs, 2021 ^28^ | BP | Low; 9 RCT | “Consumption of the vegan diet was associated with non-statistically significant reductions in SBP and DBP compared with the consumption of comparator diets.”

Abbreviations. BP=blood pressure; DBP=diastolic blood pressure; SBP=systolic blood pressure.