# RESULTS

## LITERATURE FLOW DIAGRAM

The literature flow diagram summarizes the results of the study selection process. A full list of excluded studies is provided in the Appendix.

Abbreviations. CVD=cardiovascular disease.

## OVERVIEW OF INCLUDED STUDIES

We identified 2,309 potentially relevant citations. After applying the inclusion and exclusion criteria to the 2,309 titles, 559 abstracts were reviewed. From these, a total of 239 abstracts were excluded based on several criteria related to study design, population, focus, and topic. At the full-text stage, 320 publications were reviewed. From these, 292 publications were excluded for the following reasons: did not grade evidence (N = 251), study design (N = 19), and cardiovascular disease topic other than blood pressure/hypertension (N = 22). A full list of excluded reviews from the full-text review is included in the Appendix. We included 28 publications in the maps.

### Characteristics of Included Reviews and Their Conclusions

The 28 included systematic reviews drew 52 individual conclusions. These conclusions can be categorized into 6 dietary patterns of interest and 22 clinical topic areas or outcomes of interest.

Of the 52 conclusions, 22 were drawn from 14 included reviews for the MD, 16 conclusions from 9 included reviews for the DASH diet, 5 conclusions from 5 included reviews for the DII, 5 conclusions from 4 included reviews for the vegetarian/plant-based diet, 3 conclusions from 3 included reviews for the anti-inflammatory diet, and 1 conclusion from 1 included review for the vegan diet (see Table 1).

Among the reviews that met our inclusion criteria with moderate or high certainty of evidence, 7 considered the Mediterranean diet, 7 considered the DASH diet, 3 considered the DII, and 2 considered vegetarian/plant-based diets, for a total of 19 conclusions.

The 52 conclusions could also be categorized into 22 clinical topic areas or outcomes: all-cause mortality and cancer mortality – general (N = 1 conclusion), all-cause mortality (N = 7), blood pressure (N = 10), cancer mortality – general (N = 4), cancer risk – general (N = 1), cancer risk – general and cancer mortality – general (N = 1), cognitive function (N = 2), depressive symptoms (N = 1), NAFLD and cirrhosis (N = 2), NAFLD, cirrhosis, and liver cancer (N = 1), neurodegenerative disease risk (N = 1), rheumatoid arthritis (N = 1), rheumatoid arthritis – pain (N = 1), risk of breast cancer (N = 1), risk of colorectal cancer (N = 6), risk of frailty (N = 3), risk of liver cancer (N = 2), risk of pancreatic cancer (N = 1), risk of upper GI cancer (N = 2), sarcopenia (N = 1), ulcerative colitis (N = 2), and various liver disease outcomes (N = 1).

The conclusions for clinical topic areas were grouped by diet, resulting in 6 maps (Figure 1–Figure 6), each representing a different diet. Of the conclusions, 7 had high certainty of evidence, 18 had moderate certainty of evidence, and 27 had low or very low certainty of evidence. The number of studies supporting each conclusion in the included reviews ranged from 1 study to 35 studies.

Table 1 A Crosswalk of Systematic Review Conclusions to Diets

Author, Year | Total | MD | DASH | DII | Vegetarian/Plant-Based | Anti-Inflammatory | Vegan
Ali Mohsenpour, 2019 ^21^ | 2 | | 2
Bloomfield, 2015 ^22^ | 1 | 1
Bloomfield, 2016 ^23^ | 5 | 5
Buzzetti, 2021 ^24^ | 1 | 1
Diao, 2023 ^25^ | 1 | | | 1
Filippou, 2020 ^26^ | 1 | | 1
Filippou, 2021 ^27^ | 1 | 1
Gibbs, 2021 ^28^ | 4 | 1 | 1 | | 1 | | 1
Guo, 2021 ^29^ | 1 | | | 1
Jabri, 2021 ^30^ | 1 | | | | 1
Jafari, 2022 ^31^ | 1 | | | | 1
Lee, 2020 ^32^ | 1 | | | | 1
Limketkai, 2019 ^33^ | 1 | | | | | 1
Limketkai, 2022 ^34^ | 1 | | | | | 1
Moazzen, 2020 ^35^ | 2 | 1 | | 1
Moazzen, 2021 ^36^ | 3 | 1 | 1 | 1
Morze, 2020 ^37^ | 5 | | 5
Morze, 2021 ^38^ | 2 | 2
Nelson, 2020 ^39^ | 1 | 1
Nowson, 2018 ^40^ | 2 | 2
Poursalehi, 2023 ^41^ | 2 | 2
Quirk, 2013 ^42^ | 1 | 1
Schonenberger, 2021 ^43^ | 1 | | | | | 1
Schwingshackl, 2019 ^44^ | 1 | | 1
Soltani, 2019 ^45^ | 1 | 1
Soltani, 2020 ^46^ | 2 | | 2
Theodoridis, 2023 ^47^ | 1 | | 1
Zheng, 2022 ^48^ | 5 | 2 | 2 | 1
Total included conclusions | 51 | 22 | 16 | 5 | 4 | 3 | 1

Abbreviations. DASH=Dietary Approaches to Stop Hypertension; DII=Dietary Inflammatory Index; MD=Mediterranean diet.