# METHODS

## TOPIC DEVELOPMENT

This topic was developed in response to a nomination from Tessa Johnson, MS, RDN, IFNCP, RYT, Nutrition and Food Service Clinical Nutrition Committee, Integrative and Functional Nutrition Workgroup; Katherine Dignan, MS, RD, LD, CDCES, Nutrition and Food Service Clinical Nutrition Committee, Integrative and Functional Nutrition Workgroup; Kwynn Mason, MPH, RDN, LDN, CLS, IFNCP, Nutrition and Food Service Clinical Nutrition Committee, Integrative and Functional Nutrition Workgroup; and Glory Rodriguez-Gomez, MS, RDN, CDCES, LD, IFNCP, Nutrition and Food Service Clinical Nutrition Committee, Integrative and Functional Nutrition Workgroup.

The scope was further developed with input from the topic nominator, the ESP Coordinating Center, and the review team. The scope of this report includes: 1) one or more evidence maps that provide a visual overview of the distribution of evidence for the role of anti-inflammatory dietary patterns on the prevention and management of chronic health conditions, excluding diabetes, obesity, and cardiovascular disease, and 2) an accompanying narrative that helps stakeholders interpret the state of the evidence to inform policy and clinical decision-making. A draft version of this report was reviewed by external peer reviewers; their comments and author responses are located in the Appendix.

## KEY QUESTIONS AND ELIGIBILITY CRITERIA

The aim of this synthesis is to develop evidence maps that provide a visual overview of the distribution of evidence for the role of anti-inflammatory dietary patterns on the prevention and management of chronic health conditions, excluding diabetes, obesity, and cardiovascular disease, with accompanying narrative that helps stakeholders interpret the state of the evidence to inform policy and clinical decision-making. We will focus on clinical topic areas where anti-inflammatory diet and related interventions are not yet established as one standard of care.

## STUDY SELECTION

Titles of potentially eligible reviews were screened in duplicate for relevance by 5 authors independently; any article chosen by at least 1 reviewer based on the title went on for abstract screening. Abstracts were then reviewed in duplicate, with any discrepancies resolved by group discussion. All titles and abstracts were selected based on the eligibility criteria described in the section below.

To further define the scope by clinical topic areas and outcomes of interest, we recorded condition type when initially reviewing abstracts and presented a preliminary evidence mapping of clinical topic areas and diets for which we found reviews to the operational partners to determine which areas were of interest to the VA; clinical topic areas not selected by the operational partners were therefore excluded from further review. Operational partners elected to focus on clinical topic areas other than body weight, obesity, diabetes, and most cardiovascular diseases—as described in the next paragraph—because an extensive body of literature has provided moderate to high certainty evidence of an association between adopting anti-inflammatory dietary patterns and endpoints related to these conditions, and these dietary patterns have been widely incorporated into health practitioners’ guidelines as recommendations to prevent or manage these outcomes.^15^

We included reviews on hypertension, including the continuous measure of blood pressure (BP), in our map, as hypertension has been shown to be a strong predictor of many non-cardiovascular related chronic conditions (eg, dementia, cancer);^16^ synthesizing evidence on diet and hypertension could provide important insights on the relationship between dietary patterns and other (non-cardiovascular) chronic conditions, where evidence is still lacking, to drive the use of dietary interventions to reduce the disease burden.^15,17^ With the exception of including reviews on BP, we did not include studies in which the only outcomes were intermediary outcomes or biomarkers.

We further restricted eligibility to reviews that used formal methods to assess the certainty of the evidence for conclusions. Most reviews that assessed the certainty of evidence used the widely accepted Grading of Recommendations, Assessment, Development and Evaluations (GRADE) approach.^18^ However, other formal methods were accepted, such as the approach developed by the Agency for Healthcare Research & Quality (AHRQ) Evidence-based Practice Center (EPC) program^19^ and Nutrigrade.^20^ To remain eligible, a systematic review had to 1) state or cite the method used to formally assess the certainty of included evidence, and 2) report the certainty of evidence for the effect of the dietary pattern on an outcome of interest. The assessment needed to be applied to specific conclusions, not individual studies or multiple combined conclusions.

## ELIGIBILITY CRITERIA

The ESP included studies that met the following criteria:

| Eligibility Criteria
Population | Adults (ie, individuals over 18 years old), either reported on exclusively or both adult and pediatric populations but reported results specifically for adults, were included.
Intervention | - Studies that considered anti-inflammatory dietary patterns, including the MD, DASH (not DASH low sodium), Mediterranean-Dietary Approaches to Stop Hypertension Intervention for Neurodegenerative Delay (MIND), and plant-based/vegetarian, were included.^a^; - Studies that focus on supplements, specific ingredients (eg, olive oil), eating habits, or on diets that are generic without a specific diet intervention (eg, terms like “dietary support,” “process,” and “dietary factors”) and dietary patterns that are not considered anti-inflammatory are excluded.; - Reviews that included studies of other interventions were eligible if results for specific anti-inflammatory diets were reported separately (eg, a review comparing various types of lifestyle interventions, including anti-inflammatory diets, aimed at lowering risk for breast cancer).
Comparator | No determination about eligibility was made based on comparators.
Outcomes | - Prevention and management of chronic health conditions excluding diabetes (including gestational diabetes, metabolic syndrome), obesity (including weight), and cardiovascular disease (eg, myocardial infarction, angina, heart failure, and stroke). We included hypertension/BP, as described in the narrative above.; - We included clinically relevant outcomes (including biomarkers) for conditions of interest. Biomarkers were required to be commonly used in clinical decision making, otherwise they were excluded (eg, liver enzymes for nonalcoholic fatty liver disease, or NAFLD).
Study Design | - Systematic reviews were included.; - Reviews of reviews (eg, umbrella reviews) and reviews that did not employ traditional systematic review methods (eg, narrative reviews, scoping reviews) for identifying and critically appraising studies were excluded.

Notes.

a Due to a lack of consensus on the criteria defining an anti-inflammatory diet, the decision regarding which diets to include was made by the research team in consultation with several subject matter experts and was approved by the Clinical Nutrition Committee.

## SEARCHING AND SCREENING

Search strategies were developed in consultation with a medical librarian who is expert in literature reviews. We used a combination of MeSH keywords (eg, anti-inflammat*, DASH, Mediterranean, MIND, vegetarian, plant-based, vegan) and conducted searches from inception to July 2023 in bibliographic databases (Medline, Cumulated Index to Nursing and Allied Health Literature [CINAHL], Cochrane Database of Systematic Reviews [CDSR]), non-bibliographic databases (Canadian Agency for Drugs and Technologies in Health [CADTH], National Center for Biotechnology Information [NCBI] Bookshelf, VA Dimensions), and in PROSPERO for reviews in development (see Appendix for complete search strategies). Additional citations were identified from hand-searching reference lists and consultation with content experts. English-language titles, abstracts, and full-text articles were independently reviewed by 2 investigators, and disagreements were resolved by consensus.

## DATA ABSTRACTION

Data were abstracted from each included systematic review by 1 reviewer and verified by a second reviewer. Abstracted data included, but were not limited to, descriptors to assess publication relevance and critical information about relevant conclusions. Because many systematic reviews covered a range of clinical topics, diets, or populations, we focused our data abstraction on relevant certainty of evidence conclusions rather than entire systematic reviews. For each conclusion, we determined the following: certainty of evidence assessment, study design for studies used in reaching conclusion, number of studies used in reaching conclusion, description of clinical topic area, dietary pattern or intervention characteristics, and the conclusion itself.

## SYNTHESIS

Our evidence mapping process resulted in a visual depiction of the evidence for the role of anti-inflammatory dietary patterns on the prevention and management of chronic health conditions, excluding diabetes, obesity, and cardiovascular disease, as well as an accompanying narrative and table. Each visual depiction or evidence map uses a bubble plot format to display information on 5 dimensions: bubble size (size of study/studies), bubble shape/color (study design[s]), bubble label (condition), x-axis (reported benefit vs no benefit), and y-axis (certainty of evidence). Each bubble represents a conclusion from an included systematic review. Thus, a systematic review may be represented multiple times, either in 1 map or multiple maps, but each conclusion appears only once. The maps provide the following types of information about each included conclusion from a systematic review, with each map representing a different diet:

Number of articles used to formulate conclusion (bubble size): The size of each bubble corresponds to the number of relevant primary research studies used to formulate the specific conclusion from a systematic review. Overlap between primary studies included in reviews (ie, that would be represented in more than 1 bubble) is discussed narratively.

Clinical topic area (bubble label): Each bubble is labeled with the clinical topic area discussed by that conclusion.

Shapes and colors: Included study characteristics for each conclusion are presented using colors and shapes: a yellow square denotes that this conclusion was based on observational studies only, a blue triangle denotes that this conclusion was based on randomized control trials only, and a green diamond denotes that this conclusion was based on a mix of the 2 study designs.

Strength of findings (y-axis): Each conclusion is plotted on the map based on the certainty of evidence statement as reported in the systematic review. We have 3 categories: “Conclusion is rated as low or very low certainty,” Conclusion is rated moderate certainty,” and “Conclusion is rated as high or strong certainty.”

Dietary pattern or intervention (x-axis): Each conclusion is plotted as showing either “potential benefit” or “no benefit.”

Accompanying each map is a narrative synthesis that expands upon the visual evidence map to provide a summary of high and moderate conclusions from the map and a table of conclusions organized by health condition. The narrative does not discuss low and very low certainty of evidence conclusions, because the level of certainty or strength of these conclusions is not sufficient to consider them as supporting or not supporting the conclusions (the benefit or lack of benefit of the dietary pattern). The GRADE definition of low certainty of evidence is “Our confidence in the effect estimate is limited. The true effect may be substantially different from the estimate of effect.” The definition of very low certainty of evidence is “We have very little confidence in the effect estimate: The true effect is likely to be substantially different from the estimate of effect.”^18^ Implicit in these definitions is that there is a (very) high likelihood that new evidence could change the conclusion. Details about all the conclusions in each map are included in the corresponding table.