# BACKGROUND

Chronic health conditions include heart disease, cancer, diabetes, chronic pain, asthma, inflammatory gastrointestinal disorders, degenerative diseases, obesity, and Alzheimer’s disease/dementia. Six out of 10 adults in the United States have at least 1 chronic condition, and chronic diseases are the nation’s leading cause of death and disability (causing 7 in 10 deaths each year).^1^

## Nutrition and Chronic Disease

Research on the role of diet, particularly the role of saturated fat, in the risk for and progression of chronic diseases dates as far back as World War II, with the landmark study of Keys.^2^ The 1977 report of the US Senate Select Committee on Nutrition and Human Needs (the McGovern Report) represents the first attempt of the federal government to set dietary goals to address chronic diseases among the US population.^3^ As of 2024, studies attempting to assess the role of dietary patterns and individual nutrients in specific chronic diseases as well as chronic disease in general number in the thousands, yet the strength of the evidence regarding which dietary patterns and nutrients have the greatest impact—and by what mechanisms—remains unclear.

Since the mid-2000s, the Food and Nutrition Board of the National Academy of Sciences’ Health and Medicine Division, which is responsible for developing the Dietary Reference Intakes (DRIs), has been focusing on methods for including chronic disease endpoints in determining DRIs.^4^ However, major barriers must be overcome to design and execute studies of sufficient quality to establish a body of work that can be judged to provide at least moderate evidence. Thus, the nutrition community has been faced with basing dietary guidelines for chronic disease management on the best available evidence, largely prospective cohort studies of relatively short-term duration assessing shorter term indicators of chronic disease.

## Inflammation and Chronic Disease

Inflammation can be defined in various ways but basically refers to a normal, localized or systemic physiologic process in which the mammalian immune system initiates a series of orchestrated events, including reddening, swelling, and increasing temperature, often in response to acute injury or infection.^5^ Inflammation can be acute or chronic.

Over at least the past quarter century, indirect evidence has increasingly supported an association between (chronic) inflammation and most if not all chronic diseases, including cancer, cardiovascular disease, degenerative joint diseases, Type 2 diabetes, and cognitive decline associated with aging.^6^ Although mechanisms for these associations have been proposed and are the subject of extensive research, direct evidence is generally lacking. Whether inflammation is a cause or consequence of various disease processes remains unclear, and animal models are limited in their application to human disease.

## Anti-Inflammatory Diet and Chronic Disease

Despite the lack of understanding of the mechanisms by which inflammation might increase the risk for or the progression of chronic diseases, some evidence suggests that some nutrients, eg, simple carbohydrates and saturated fat, may promote inflammation. Likewise, some dietary patterns have been associated with chronic disease risk.^7^ A high level of evidence from randomized controlled trials supports the role of the DASH (Dietary Approaches to Stop Hypertension) eating plan in preventing and managing hypertension.^8^ The DASH diet emphasizes higher intakes of fruits, vegetables, whole grains, beans, lean meats, fish, and low-fat dairy foods, and limited intakes of saturated fats, refined carbohydrates, sweets, and sodium; it is also rich in the minerals potassium, calcium, and magnesium, as well as in dietary fiber and protein compared with the average US diet. The DASH plan was not developed as an anti-inflammatory diet, and whether this diet exerts its effects through an anti-inflammatory mechanism is unclear, but it closely resembles dietary patterns identified as anti-inflammatory and is likely the most thoroughly studied diet in terms of research quality.

Likewise, evidence from population studies dating back to the late 1950s seems to support an association between what has come to be known as the Mediterranean diet (MD) and reduced risk for cardiovascular disease and other chronic conditions.^9^ The MD pattern (based originally on eating patterns identified in Italy and Greece) has been characterized as one that emphasizes high intakes of fruits, vegetables, legumes, grains, unsaturated fats, moderate intakes of fish, and lower intakes of meats and dairy foods. Measuring adherence to the MD has spawned at least 4 different methods or indices, including the Alternate Mediterranean Diet, the Mediterranean-Style Dietary Pattern Score (MSDPS), the Mediterranean Diet Score, and the Mediterranean Diet Adherence Screener, some food based and some nutrient based.^10^ The MSDPS attempts to calculate intakes of more than 20 nutrients: energy, dietary fiber, glycemic index, added sugar, b-carotene, lycopene, folate, vitamins C and E, calcium, magnesium, potassium, alcohol, saturated and trans fats, monounsaturated fat, oleic acid, polyunsaturated fatty acids (FA), omega-6 (n-6) FA, omega-3 (n-3) FA, linoleic acid, linolenic acid, n-6/n-3 ratio, and the combination of two n-3 FA, eicosapentaenoic acid (EPA) and docosahexaenoic acid (DHA).

Finally, some evidence has shown an association between adherence to various vegetarian diets and vegan (plant-based) diets and risk for chronic disease. One mechanism that has been proposed to explain how each of these diets might lower disease risk is via anti-inflammatory properties of some or all of the nutrients or the absence of other nutrients.

## What Are Dietary Patterns and What Is the Definition of an Anti-Inflammatory Diet?

A challenge in conducting research on the role of nutrition in health is that the traditional focus on single nutrients ignores the importance of nutrient interactions and overall dietary patterns—the totality of what individuals and groups tend to eat over time; thus, current research increasingly has focused on the role of overall diet. The 2010 Dietary Guidelines for Americans^11^ (DGA) report introduced the concept of assessing the role of overall dietary patterns—the kinds of foods people tend to eat—in morbidity and mortality. Prior to that report, the DGA (which is issued every 5 years) had focused on individual nutrients and their roles in health and disease. But the 2010 DGA report drew few conclusions about the role of dietary patterns beyond the need to increase focus on them, because, as the committee acknowledged, they are exceedingly difficult to measure with any precision. And because they are difficult to measure, it is even more challenging to try to establish a causal relationship with any health outcomes. Following release of the 2010 DGA, the Dietary Patterns Methods Project was launched. This project has sought to gather or establish methods to score adherence of an individual’s or population’s food intake to a particular diet or standard, such as the DASH diet score, the MD score, the Healthy Eating Index, and the Dietary Inflammatory Index (DII).^12^ The 2015 DGA sought to focus mainly on the association of dietary patterns and health outcomes, while acknowledging that individual nutrients could interact—either in opposition or in synergy—and that particular foods could affect the bioavailability of the nutrients contained within them or in other foods in ways that cannot be accounted for.^13^

The Dietary Patterns Subcommittee of the 2020 Dietary Guidelines Committee (DGC) conducted a systematic review of the associations of various dietary patterns with all-cause mortality, in collaboration with United States Department of Agriculture’s systematic review team.^14^ The review, which included 153 articles, reported:

“Strong evidence demonstrates that dietary patterns in adults and older adults characterized by vegetables, fruits, legumes, nuts, whole grains, unsaturated vegetable oils, and fish, lean meat or poultry when meat was included, are associated with decreased risk of all-cause mortality. These patterns were also relatively low in red and processed meat, high-fat dairy, and refined carbohydrates or sweets. Some of these dietary patterns also included alcoholic beverages in moderation.”

Of the studies included in the 2020 DGC review, one assessed adherence to the DII, and several others considered anti-inflammatory diet properties as exposures. However, the report did not draw specific conclusions on the impact of an anti-inflammatory diet as such. Numerous included studies investigated the DASH diet, vegetarian, and vegan dietary patterns.

What exactly is an anti-inflammatory diet or dietary pattern? The DII is based on evidence gathered from studies—cross-sectional and cohort—on the association between intakes of any nutrient (and presumptive nutrients like some phytochemicals) and levels of 6 inflammatory biomarkers: interleukin (IL)-1β, IL-4, IL-6, IL10, Tumor Necrosis Factor (TNF)-α, and C-reactive protein (CRP).^12^ The original DII, developed in 2009, was updated in 2014 to include more studies and refine some aspects of the algorithm. The current DII comprises 45 food component parameters, including (but not limited to) mono- and polyunsaturated fatty acids, fiber, most of the known vitamins and minerals, other antioxidants, phytochemicals that include flavonoids and anthocyanins, caffeine, cholesterol, macronutrients, alcohol, and green and black tea. Particular foods are considered anti-inflammatory (eg, fatty fish, nuts, berries), whereas others are considered pro-inflammatory (eg, processed meats, foods high in saturated fat, sugar-sweetened beverages, refined grains), as discussed above. Thus, several other dietary patterns, including the DASH diet, MD, and some vegetarian and vegan diets, are anti-inflammatory.

## This Evidence Map

In response to increasing interest in the potential role for anti-inflammatory diets as a standard of care for preventing and managing chronic disease, the Veterans Health Administration (VHA) Clinical Nutrition Committee requested a review of reviews (evidence map) of available evidence on the health effects of anti-inflammatory diets. The current body of literature—and literature reviews—on this topic is large, particularly in the areas of cardiovascular disease, diabetes, and obesity. Benefits of anti-inflammatory diets in preventing and managing these conditions is widely accepted, as evidenced by recommendations of organizations like the American Diabetes Association, the American Heart Association, and the Academy of Nutrition and Dietetics to follow diets such as the Mediterranean diet and the DASH diet. Therefore, to make the body of evidence more manageable for evidence maps, we chose to focus on conditions that may have been less studied but are of considerable importance for the VA population, including cancer, chronic pain, liver disease, and frailty. Thus, the purpose of this map was to catalog existing systematic reviews in areas of interest with less established bodies of research and to identify evidence gaps.

Findings from this review will be used by the Clinical Nutrition Committee to inform the development of clinical guidance for dietitians and the clinical team. Guidance will include national education calls, training courses for VA staff, and national education materials for Veterans. Additionally, the evidence will inform the development of standards for anti-inflammatory diet classes for Veterans. Lastly, evidence will support the Eating for Whole Health faculty (of the Office of Patient Centered Care and Cultural Transformation) to improve the nutrition courses that are taught and developed for all VA staff.