# Appendix

## SEARCH STRATEGIES

Search Date: July 25, 2023
1. Bibliographic Databases | # | Search Statement | Results
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process, In-Data-Review & Other Non-Indexed Citations and Daily 1946 to July 25, 2023 | 1 | Mediterranean Diet/ OR Diet, Vegetarian/ OR Diet, Vegan/ | 9322
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process, In-Data-Review & Other Non-Indexed Citations and Daily 1946 to July 25, 2023 | 2 | (((anti-inflammat* OR DASH OR Mediterranean OR MIND OR vegetarian OR plant?based OR vegan) adj3 diet*) OR MedDiet).ti,ab,kf,kw. | 13174
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process, In-Data-Review & Other Non-Indexed Citations and Daily 1946 to July 25, 2023 | 3 | 1 OR 2 | 16155
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process, In-Data-Review & Other Non-Indexed Citations and Daily 1946 to July 25, 2023 | 4 | (systematic review.ti. or meta-analysis.pt. or meta-analysis.ti. or systematic literature review.ti. or this systematic review.tw. or pooling project.tw. or (systematic review.ti,ab. and review.pt.) or meta synthesis.ti. or meta-analy*.ti. or integrative review.tw. or integrative research review.tw. or rapid review.tw. or umbrella review.tw. or consensus development conference.pt. or practice guideline.pt. or drug class reviews.ti. or cochrane database syst rev.jn. or acp journal club.jn. or health technol assess.jn. or evid rep technol assess summ.jn. or jbi database system rev implement rep.jn. or (clinical guideline and management).tw. or ((evidence based.ti. or evidence-based medicine/ or best practice*.ti. or evidence synthesis.ti,ab.) and (((review.pt. or diseases category/ or behavior.mp.) and behavior mechanisms/) or therapeutics/ or evaluation studies.pt. or validation studies.pt. or guideline.pt. or pmcbook.mp.)) or (((systematic or systematically).tw. or critical.ti,ab. or study selection.tw. or ((predetermined or inclusion) and criteri*).tw. or exclusion criteri*.tw. or main outcome measures.tw. or standard of care.tw. or standards of care.tw.) and ((survey or surveys).ti,ab. or overview*.tw. or review.ti,ab. or reviews.ti,ab. or search*.tw. or handsearch.tw. or analysis.ti. or critique.ti,ab. or appraisal.tw. or (reduction.tw. and (risk/ or risk.tw.) and (death or recurrence).mp.)) and ((literature or articles or publications or publication or bibliography or bibliographies or published).ti,ab. or pooled data.tw. or unpublished.tw. or citation.tw. or citations.tw. or database.ti,ab. or internet.ti,ab. or textbooks.ti,ab. or references.tw. or scales.tw. or papers.tw. or datasets.tw. or trials.ti,ab. or meta-analy*.tw. or (clinical and studies).ti,ab. or treatment outcome/ or treatment outcome.tw. or pmcbook.mp.))) not (letter or newspaper article).pt. | 606863
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process, In-Data-Review & Other Non-Indexed Citations and Daily 1946 to July 25, 2023 | 5 | 3 AND 4 | 944
CINAHL Ultimate | 1 | (MH “Mediterranean Diet”) OR (MH “Vegetarianism”) OR (MH “Plant-Based Diet”) | 12723
CINAHL Ultimate | 2 | TX (((anti-inflammat* OR DASH OR Mediterranean OR MIND OR vegetarian OR plant?based OR vegan) N3 diet*) OR MedDiet) | 26079
CINAHL Ultimate | 3 | 1 OR 2 | 31579
CINAHL Ultimate | 4 | (MH “meta analysis” OR MH “systematic review” OR MH “Technology, Medical/EV” OR PT “systematic review” OR PT “meta analysis” OR (((TI systematic* OR AB systematic*) N3 ((TI review* OR AB review*) OR (TI overview* OR AB overview*))) OR ((TI methodologic* OR AB methodologic*) N3 ((TI review* OR AB review*) OR (TI overview* OR AB overview*)))) OR (((TI quantitative OR AB quantitative) N3 ((TI review* OR AB review*) OR (TI overview* OR AB overview*) OR (TI synthes* OR AB synthes*))) OR ((TI research OR AB research) N3 ((TI integrati* OR AB integrati*) OR (TI overview* OR AB overview*)))) OR (((TI integrative OR AB integrative) N3 ((TI review* OR AB review*) OR (TI overview* OR AB overview*))) OR ((TI collaborative OR AB collaborative) N3 ((TI review* OR AB review*) OR (TI overview* OR AB overview*))) OR ((TI pool* OR AB pool*) N3 (TI analy* OR AB analy*))) OR ((TI “data synthes*” OR AB “data synthes*”) OR (TI “data extraction*” OR AB “data extraction*”) OR (TI “data abstraction*” OR AB “data abstraction*”)) OR ((TI handsearch* OR AB handsearch*) OR (TI “hand search*” OR AB “hand search*”)) OR ((TI “mantel haenszel” OR AB “mantel haenszel”) OR (TI peto OR AB peto) OR (TI “der simonian” OR AB “der simonian”) OR (TI dersimonian OR AB dersimonian) OR (TI “fixed effect*” OR AB “fixed effect*”) OR (TI “latin square*” OR AB “latin square*”)) OR ((TI “met analy*” OR AB “met analy*”) OR (TI metanaly* OR AB metanaly*) OR (TI “technology assessment*” OR AB “technology assessment*”) OR (TI HTA OR AB HTA) OR (TI HTAs OR AB HTAs) OR (TI “technology overview*” OR AB “technology overview*”) OR (TI “technology appraisal*” OR AB “technology appraisal*”)) OR ((TI “meta regression*” OR AB “meta regression*”) OR (TI metaregression* OR AB metaregression*)) OR (MW meta-analy* OR MW metaanaly* OR MW “systematic review*” OR MW “biomedical technology assessment*” OR MW “biomedical technology assessment*”) OR ((TI medline OR AB medline OR MW medline) OR (TI cochrane OR AB cochrane OR MW cochrane) OR (TI pubmed OR AB pubmed OR MW pubmed) OR (TI medlars OR AB medlars OR MW medlars) OR (TI embase OR AB embase OR MW embase) OR (TI cinahl OR AB cinahl OR MW cinahl)) OR (SO Cochrane OR SO health technology assessment OR SO evidence report) OR ((TI comparative OR AB comparative) N3 ((TI efficacy OR AB efficacy) OR (TI effectiveness OR AB effectiveness))) OR ((TI “outcomes research” OR AB “outcomes research”) OR (TI “relative effectiveness” OR AB “relative effectiveness”)) OR (((TI indirect OR AB indirect) OR (TI “indirect treatment” OR AB “indirect treatment”) OR (TI mixed-treatment OR AB mixed-treatment) OR (TI bayesian OR AB bayesian)) N3 (TI comparison* OR AB comparison*)) OR ((TI multi* OR AB multi*) N3 (TI treatment OR AB treatment) N3 (TI comparison* OR AB comparison*)) OR ((TI mixed OR AB mixed) N3 (TI treatment OR AB treatment) N3 ((TI metaanaly* OR AB meta-analy*) OR (TI metaanaly* OR AB metaanaly*))) OR (TI “umbrella review*” OR AB “umbrella review*”) OR ((TI multi* OR AB multi*) N2 (TI paramet* OR AB paramet*) N2 (TI evidence OR AB evidence) N2 (TI synthesis OR AB synthesis)) OR ((TI multiparamet* OR AB multiparamet*) N2 (TI evidence OR AB evidence) N2 (TI synthesis OR AB synthesis)) OR ((TI multi-paramet* OR AB multi-paramet*) N2 (TI evidence OR AB evidence) N2 (TI synthesis OR AB synthesis)) | 310465
| 5 | 3 AND 4 | 1812
CDSR: Protocols and Reviews; April 1996-present | 1 | MeSH descriptor: [Diet, Mediterranean] this term only | 768
CDSR: Protocols and Reviews; April 1996-present | 2 | MeSH descriptor: [Diet, Vegetarian] this term only | 242
CDSR: Protocols and Reviews; April 1996-present | 3 | MeSH descriptor: [Diet, Vegan] this term only | 38
CDSR: Protocols and Reviews; April 1996-present | 4 | (((anti-inflammat* OR DASH OR Mediterranean OR MIND OR vegetarian OR plant?based OR vegan) near/3 diet*) OR MedDiet) | 4013
CDSR: Protocols and Reviews; April 1996-present | 5 | #1 OR #2 OR #3 OR #4 | 4013
CDSR: Protocols and Reviews; April 1996-present | 6 | Limit 5 to protocols and reviews | 76
Bibliographic databases
Total results | | | 2832
2. Non-Bibliographic Databases | Search Statement/Description | | Results
AHRQ: evidence reports, technology assessments, U.S Preventative Services Task Force Evidence Synthesis (http://www.ahrq.gov/research/findings/evidence-based-reports/search.html) | Mediterranean diet OR vegan diet OR vegetarian diet OR DASH diet OR plant-based diet OR anti-inflammatory diet | | 0
CADTH (https://www.cadth.ca/) | Mediterranean diet OR vegan diet OR vegetarian diet OR DASH diet OR plant-based diet OR anti-inflammatory diet; Anti-inflammatory Diets for Chronic, Non-Cancer Pain: Clinical Effectiveness and Guidelines (https://www.cda-amc.ca/301-archived-content); Nutritional Interventions for the Delayed Progression or Reversal of Frailty: Clinical Effectiveness (https://www.cadth.ca/nutritional-interventions-delayed-progression-or-reversal-frailty-clinical-effectiveness); Low Carbohydrate Diets for Diabetes: A Review of the Clinical Effectiveness and Guidelines (https://www.cda-amc.ca/301-archived-content); Dietary Interventions for Chronic Kidney Disease (https://www.cda-amc.ca/301-archived-content) | | 4
EPPI-Centre (http://eppi.ioe.ac.uk/cms/Default.aspx?tabid=62) | [Use browser search function [CNTL + F] for keyword search]; Mediterranean diet OR vegan diet OR vegetarian diet OR DASH diet OR plant-based diet OR anti-inflammatory diet | | 0
NCBI Bookshelf (http://www.ncbi.nlm.nih.gov/books) | Mediterranean diet OR vegan diet OR vegetarian diet OR DASH diet OR plant-based diet OR anti-inflammatory diet; Benefits and Harms of the Mediterranean Diet Compared to Other Diets [Internet]. (https://www.ncbi.nlm.nih.gov/books/NBK379574/?term=Mediterranean%20diet%20OR%20vegan%20diet%20OR%20vegetarian%20diet%20OR%20DASH%20diet%20OR%20plant-based%20diet%20OR%20anti-inflammatory%20diet); What National and Subnational Interventions and Policies Based on Mediterranean and Nordic Diets are Recommended or Implemented in the WHO European Region, and is there Evidence of Effectiveness in Reducing Noncommunicable Diseases? [Internet]. (https://www.ncbi.nlm.nih.gov/books/NBK519076/?term=Mediterranean%20diet%20OR%20vegan%20diet%20OR%20vegetarian%20diet%20OR%20DASH%20diet%20OR%20plant-based%20diet%20OR%20anti-inflammatory%20diet); Diet and Health: Implications for Reducing Chronic Disease Risk. (https://www.ncbi.nlm.nih.gov/books/NBK218743/?term=Mediterranean%20diet%20OR%20vegan%20diet%20OR%20vegetarian%20diet%20OR%20DASH%20diet%20OR%20plant-based%20diet%20OR%20anti-inflammatory%20diet) | | 3
NHS Evidence (http://www.evidence.nhs.uk/default.aspx) | Not available
VA: HSR&D (http://www.hsrd.research.va.gov/research/default.cfm) | Mediterranean diet OR vegan diet OR vegetarian diet OR DASH diet OR plant-based diet OR anti-inflammatory diet | | 0
VA: ORD (http://www.research.va.gov/research_topics/) | Mediterranean diet OR vegan diet OR vegetarian diet OR DASH diet OR plant-based diet OR anti-inflammatory diet | | 0
VA: Dimensions (https://va.dimensions.ai/discover/publication) | (“Mediterranean diet” OR “vegan diet” OR “vegetarian diet” OR “DASH diet” OR “plant-based diet” OR “anti-inflammatory diet”) AND review, limit to VA publications | | 9
3. Secondary Sources | Search Statement/Description | | Results
BCBS Foundation Massachusetts (https://www.bluecrossmafoundation.org/publications) | N/A | | 0
CMS Research Reports (https://www.cms.gov/research-statistics-data-and-systems/statistics-trends-and-reports/archives/researchreports) | N/A | | 0
Hayes (https://www.hayesinc.com/category/publications/) | N/A | | 0
ICES (https://www.ices.on.ca/Publications/Atlases-and-Reports) | N/A | | 0
National Academies, Health & Medicine Division (https://nap.nationalacademies.org/author/HMD/health-and-medicine-division) | N/A | | 0
McMaster Health Systems Evidence (https://www.healthsystemsevidence.org/) | N/A | | 0
Robert Wood Johnson Foundation (https://www.rwjf.org/en/robert-wood-johnson-foundation.html) | N/A | | 0
UBC Centre for Health Services & Policy Research (https://chspr.ubc.ca/publications/) | N/A | | 0
WHO Health Evidence Network (https://www.who.int/europe/publications/i) | N/A | | 0
4. Reviews in development | Search Statement/Description | | Results
AHRD topics in development (EPC status report) | [Email Charli Armstrong Charlotte.Armstrong1@va.gov]; KV emailed 07-26-23; CA responded 07-26-23: no duplication | | 0
PROSPERO (http://www.crd.york.ac.uk/PROSPERO/) (SR registry) | Mediterranean diet OR vegan diet OR vegetarian diet OR DASH diet OR plant-based diet OR anti-inflammatory diet; A meta-analysis of effects of Mediterranean diet in patients with nonalcoholic fatty liver disease (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=267366); A systematic review of diets for weight loss and remission of type 2 diabetes (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=208878); Adherence to a Mediterranean Diet and risk of Alzheimer’s and Parkinson’s Diseases: a systematic review of population-based studies and evidence from pre-clinical studies (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=414016); Adherence to a Mediterranean -style diet and risk of diabetes: A Systematic Review and Meta-Analysis of Prospective Studies (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=265332); Adherence to DASH diet and hypertension risk: a systematic review and meta-analysis (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=344686); Adherence to Mediterranean diet and risk of cancer: a systematic review and meta-analysis of observational studies (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=4382); Adherence to the Mediterranean diet in relation to all-cause mortality: a systematic review and dose-response meta-analysis of prospective cohort studies (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=94059); Anti-Inflammatory Diets for Patients with a Chronic Inflammatory Disease: Protocol for a Systematic Review and Meta-Analysis of Randomized Trials (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=418727); Association between Mediterranean diet and Parkinson’s disease in adults: A systematic review and meta-analysis of cohort studies (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=255818); Benefits and harms of the Mediterranean diet compared to other dietary interventions (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=20262); Dietary interventions for non-alcoholic fatty liver disease: systematic review and meta-analysis (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=88824); Effectiveness of vegetarian and vegan diets in type 2 diabetes mellitus: Systematic review (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=316339); Evidence on vegan diet for health benefits and risks – an umbrella review of meta-analyses of observational and interventional studies (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=173424); Impact of Vegetarian, Vegan and Non-Vegetarian Diets on Cardiometabolic Disease Prevention, Secondary Prevention and Management in Adults (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=396453); The effectiveness of a low-fat vegan diet for the prevention and management of type 2 diabetes: a systematic review and meta-analysis of controlled trials (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=311056); Vegan and vegetarian diets vs. omnivore diets: implications on human health: a systematic review of randomized clinical trials (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=42549); Effects of vegetarian and vegan diets on insulin sensitivity in people with overweight or type 2 diabetes: protocol for a systematic review and meta-analysis (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=386744); Efficacy of Plant-based Dietary Patterns in the management of type 2 diabetes mellitus: A Systematic Review and Meta-Analysis (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=418621); Healthy effects of vegetarian diets: evidence and mechanisms (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=342073); Nutritional and health outcomes associated with vegetarian diets: an umbrella systematic review of meta-analyses (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=92470); Role of Vegetarian and Plant-based diet in the prevention of Mild Cognitive Impairment and Dementia (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=380055); Systematic review and meta-analysis of the associations of vegan and vegetarian diets with inflammatory biomarkers (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=79220); Systematic review of the relationship between vegetarian diets and health-related outcomes (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=177670); Adherence to DASH diet and hypertension risk: a systematic review and meta-analysis (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=344686); Effect of anti-inflammatory diet on NAFLD: systematic review (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=269382); Effect of anti-inflammatory diets on inflammation markers in adult human populations: a systematic review of randomized controlled trials Update 2020–2023 (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=412761); Effect of Plant-Based Diets on Rheumatoid Arthritis: A Systematic Review (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=420577); Effect of Plant-based Dietary Patterns in Type 2 Diabetes Patients: A Systematic Review of Randomized Controlled Trials (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=297702); Effect of the level of adherence to the DASH diet on blood pressure: a systematic review and meta-analysis of observational studies (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=368688); Anti-Inflammatory Diets for Patients with a Chronic Inflammatory Disease: Protocol for a Systematic Review and Meta-Analysis of Randomized Trials (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=418727); The effects of an anti-inflammatory diet on chronic inflammation and disease activity in adults diagnosed with rheumatoid arthritis (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=443844) | | 32
Summary
Bibliographic databases | | | 2832
Non-bibliographic databases | | | 16
Secondary sources | | | 0
Reviews in development | | | 32
Total results | | | 2880
Total after deduplication | | | 2309

## STUDIES EXCLUDED DURING FULL-TEXT SCREENING

### No GRADE, N = 251

1 Abbas, N., , A Systematic Review of the Role of Diet in Ulcerative Colitis. Cureus, 2023. 15(5): p. e39350.37351247
2 Abboud, M., , Effect of Ketogenic Diet on Quality of Life in Adults with Chronic Disease: A Systematic Review of Randomized Controlled Trials. Nutrients, 2021. 13(12): p. 4463–4463.34960015
3 Abdallah, J., , Effects of anti-inflammatory dietary patterns on non-alcoholic fatty liver disease: a systematic literature review. European journal of nutrition, 2023. 62(4): p. 1563–1578.36690886
4 Ajjarapu, A.S., , Dietary Patterns and Renal Health Outcomes in the General Population: A Review Focusing on Prospective Studies. Nutrients, 2019. 11(8).
5 Akhlaghi, M., M. Ghasemi-Nasab, and M. Riasatian, Mediterranean diet for patients with non-alcoholic fatty liver disease, a systematic review and meta-analysis of observational and clinical investigations. Journal of diabetes and metabolic disorders, 2020. 19(1): p. 575–584.32550210
6 Albuquerque, R.C.R., V.T. Baltar, and D.M.L. Marchioni, Breast cancer and dietary patterns: a systematic review. Nutrition reviews, 2014. 72(1): p. 1–17.
7 Alifah, K., Y.A.E. Damayanti, and A. Rahmani, 22. The Effect of DASH Diet on Blood Pressure and Metabolic Profile in Hypertensive Patients: A Systematic Review and Meta-Analysis. Journal of Hypertension, 2023. 41: p. e6–e6.
8 Alnooh, G., , The Use of Dietary Approaches to Stop Hypertension (DASH) Mobile Apps for Supporting a Healthy Diet and Controlling Hypertension in Adults: Systematic Review. JMIR cardio, 2022. 6(2): p. e35876.36322108
9 Angelidi, A.M., , The effect of dietary patterns on non-alcoholic fatty liver disease diagnosed by biopsy or magnetic resonance in adults: a systematic review of randomised controlled trials. Metabolism: clinical and experimental, 2022. 129: p. 155136.35032545
10 Aridi, Y.S., J.L. Walker, and O.R.L. Wright, The Association between the Mediterranean Dietary Pattern and Cognitive Health: A Systematic Review. Nutrients, 2017. 9(7).
11 Asbaghi, O., , Effects of the Mediterranean diet on cardiovascular risk factors in nonalcoholic fatty liver disease patients: A systematic review and meta-analysis. Clinical nutrition ESPEN, 2020. 37: p. 148–156.32359737
12 Askari, M., , Vegetarian diet and the risk of depression, anxiety, and stress symptoms: a systematic review and meta-analysis of observational studies. Critical reviews in food science and nutrition, 2022. 62(1): p. 261–271.32885996
13 Atabilen, B. and Y. Akdevelioglu, Effects of different dietary interventions in multiple sclerosis: a systematic review of evidence from 2018 to 2022. Nutritional neuroscience, 2022: p. 1–13.
14 Azzola, L.G., N. Fankhauser, and M. Srinivasan, Influence of the vegan, vegetarian and omnivore diet on the oral health status in adults: a systematic review and meta-analysis. Evidence-based dentistry, 2023. 24(1): p. 43–44.
15 Bach, K.E., , Healthy Dietary Patterns and Incidence of CKD: A Meta-Analysis of Cohort Studies. Clinical journal of the American Society of Nephrology : CJASN, 2019. 14(10): p. 1441–1449.31551237
16 Backlund, R., , Diet and the risk of rheumatoid arthritis - A systematic literature review. Seminars in arthritis and rheumatism, 2023. 58: p. 152118.36379128
17 Bäcklund, R., , Diet and the risk of rheumatoid arthritis – A systematic literature review. Seminars in Arthritis & Rheumatism, 2023. 58.
18 Bahrami, A., , Adherence to the Mediterranean diet and the risk of lung cancer: a systematic review and dose-response meta-analysis of observational studies. Nutrition reviews, 2022. 80(5): p. 1118–1128.35224641
19 Bakaloudi, D.R., , Impact of the Level of Adherence to Mediterranean Diet on the Parameters of Metabolic Syndrome: A Systematic Review and Meta-Analysis of Observational Studies. Nutrients, 2021. 13(5).
20 Bakaloudi, D.R., , Impact of the level of adherence to the Mediterranean Diet on blood pressure: A systematic review and meta-analysis of observational studies. Clinical nutrition (Edinburgh, Scotland), 2021. 40(12): p. 5771–5780.34773865
21 Balasubramaniam, J. and S.J. Hewlings, A Systematic Review of the Efficacy of DASH Diet in Lowering Blood Pressure Among Hypertensive Adults. Topics in Clinical Nutrition, 2021. 36(2): p. 158–176.
22 Ballarin-Naya, L., S. Malo, and B. Moreno-Franco, [Effect of physical exercise and diet based interventions on the evolution of cognitive impairment to dementia in subjects older than 45 years. A systematic review.]. Efecto de intervenciones basadas en ejercicio fisico y dieta sobre la evolucion de deterioro cognitivo leve a demencia en sujetos mayores de 45 anos. Revision sistematica., 2021. 95.
23 Barchitta, M., , The Effects of Diet and Dietary Interventions on the Quality of Life among Breast Cancer Survivors: A Cross-Sectional Analysis and a Systematic Review of Experimental Studies. Cancers, 2020. 12(2).
24 Bayes, J., , The effect of the Mediterranean diet on health outcomes in post-stroke adults: a systematic literature review of intervention trials. European journal of clinical nutrition, 2023. 77(5): p. 551–560.36127392
25 Bella, F., , Differences in the association between empirically derived dietary patterns and cancer: a meta-analysis. International journal of food sciences and nutrition, 2017. 68(4): p. 402–410.27894200
26 Berkow, S.E. and N.D. Barnard, Blood pressure regulation and vegetarian diets. Nutrition Reviews, 2005. 63(1): p. 1–8.15730229
27 Bianchi, V.E., P.F. Herrera, and R. Laura, Effect of nutrition on neurodegenerative diseases. A systematic review. Nutritional neuroscience, 2021. 24(10): p. 810–834.31684843
28 Bianchi, V.E., L. Rizzi, and F. Somaa, The role of nutrition on Parkinson's disease: a systematic review. Nutritional neuroscience, 2023. 26(7): p. 605–628.35730414
29 Boarin, M., , Dietary and lifestyle recommendations for urolithiasis prevention: A systematic literature review. International Journal of Urological Nursing, 2018. 12(2/3): p. 53–70.
30 Bonaccio, M., , Mediterranean diet and mortality in the elderly: a prospective cohort study and a meta-analysis. The British journal of nutrition, 2018. 120(8): p. 841–854.30157978
31 Brown, T.J., , Dietary interventions with dietitian involvement in adults with chronic kidney disease: A systematic review. Journal of human nutrition and dietetics : the official journal of the British Dietetic Association, 2021. 34(4): p. 747–757.33682964
32 Buck, A.N., , Evidence-Based Dietary Practices to Improve Osteoarthritis Symptoms: An Umbrella Review. Nutrients, 2023. 15(13).
33 Burstad, K.M., , Effects of Plant-Based Protein Consumption on Kidney Function and Mineral Bone Disorder Outcomes in Adults With Stage 3–5 Chronic Kidney Diseas : A Systematic Review. Journal of renal nutrition : the official journal of the Council on Renal Nutrition of the National Kidney Foundation, 2023.
34 Canevelli, M., , Nutrition and Dementia: Evidence for Preventive Approaches? Nutrients, 2016. 8(3): p. 144.26959055
35 Cao, L., , Dietary Patterns and Risk of Dementia: a Systematic Review and Meta-Analysis of Cohort Studies. Molecular neurobiology, 2016. 53(9): p. 6144–6154.26553347
36 Carroll, K.L., , Diet as a Risk Factor for Early-Onset Colorectal Adenoma and Carcinoma: A Systematic Review. Frontiers in nutrition, 2022. 9: p. 896330.35757246
37 Castro-Espin, C. and A. Agudo, The Role of Diet in Prognosis among Cancer Survivors: A Systematic Review and Meta-Analysis of Dietary Patterns and Diet Interventions. Nutrients, 2022. 14(2).
38 Chand, R.R., F.M. Blyth, and S. Khalatbari-Soltani, Healthy dietary indices and noncancer pain: a systematic review of cross-sectional and longitudinal studies. Pain, 2023. 164(4): p. e177–e189.36083185
39 Chapman, N.A., R.J. Jacobs, and A.J. Braakhuis, Role of diet and food intake in age-related macular degeneration: a systematic review. Clinical & experimental ophthalmology, 2019. 47(1): p. 106–127.29927057
40 Charkviani, M., , Effects of Mediterranean Diet, DASH Diet, and Plant-Based Diet on Outcomes among End Stage Kidney Disease Patients: A Systematic Review and Meta-Analysis. Clinics and practice, 2022. 13(1): p. 41–51.36648844
41 Chen, G., , The Role of the Mediterranean Diet in Breast Cancer Survivorship: A Systematic Review and Meta-Analysis of Observational Studies and Randomised Controlled Trials. Nutrients, 2023. 15(9).
42 Chen, X., , Dietary Patterns and Cognitive Health in Older Adults: A Systematic Review. Journal of Alzheimer's disease : JAD, 2019. 67(2): p. 583–619.30689586
43 Cheng, S., , Mediterranean dietary pattern and the risk of prostate cancer: A meta-analysis. Medicine, 2019. 98(27): p. e16341.31277188
44 Coelho-Junior, H.J., A. Trichopoulou, and F. Panza, Cross-sectional and longitudinal associations between adherence to Mediterranean diet with physical performance and cognitive function in older adults: A systematic review and meta-analysis. Ageing research reviews, 2021. 70: p. 101395.34153553
45 Comeche, J.M., , Predefined Diets in Patients with Inflammatory Bowel Disease: Systematic Review and Meta-Analysis. Nutrients, 2020. 13(1).
46 Coughlin, S.S., J. Stewart, and L.B. Williams, A review of adherence to the Mediterranean diet and breast cancer risk according to estrogen- and progesterone-receptor status and HER2 oncogene expression. Annals of epidemiology and public health, 2018. 1.
47 Cowell, O.R., , Effects of a Mediterranean diet on blood pressure: a systematic review and meta-analysis of randomized controlled trials and observational studies. Journal of hypertension, 2021. 39(4): p. 729–739.33060448
48 Craig, J., , The relationship between pre-defined Mediterranean dietary patterns and musculoskeletal health in all age groups: a systematic review...New technology in nutrition research and practice. Summer Meeting, 11–14 July 2016. Ireland. Proceedings of the Nutrition Society, 2016. 75(OCE3): p. 1-1.26282529
49 Craig, J.V., , Relationship between the Mediterranean dietary pattern and musculoskeletal health in children, adolescents, and adults: systematic review and evidence map. Nutrition reviews, 2017. 75(10): p. 830–857.29028268
50 Cuevas-Cervera, M., , The Effectiveness of Intermittent Fasting, Time Restricted Feeding, Caloric Restriction, a Ketogenic Diet and the Mediterranean Diet as Part of the Treatment Plan to Improve Health and Chronic Musculoskeletal Pain: A Systematic Review. International journal of environmental research and public health, 2022. 19(11).
51 Defeudis, G., , Effects of diet and antihyperglycemic drugs on erectile dysfunction: A systematic review. Andrology, 2023. 11(2): p. 282–294.35485604
52 Del Bo, C., , Does the Mediterranean Diet Have Any Effect on Lipid Profile, Central Obesity and Liver Enzymes in Non-Alcoholic Fatty Liver Disease (NAFLD) Subjects? A Systematic Review and Meta-Analysis of Randomized Control Trials. Nutrients, 2023. 15(10).
53 Deng, Y., , [Association between adherence to three healthy dietary patterns and risk of cognitive disorders:Meta-analysis]. Wei sheng yan jiu = Journal of hygiene research, 2022. 51(5): p. 725–732.36222032
54 Devranis, P., , Mediterranean Diet, Ketogenic Diet or MIND Diet for Aging Populations with Cognitive Decline: A Systematic Review. Life (Basel, Switzerland), 2023. 13(1).
55 Di Francesco, S. and R.L. Tenaglia, Mediterranean diet and erectile dysfunction: a current perspective. Central European journal of urology, 2017. 70(2): p. 185–187.28721287
56 Dianatinasab, M., , Dietary patterns and risk of bladder cancer: a systematic review and meta-analysis. BMC public health, 2022. 22(1): p. 73.35016647
57 Dianatinasab, M., , Dietary Patterns and Risk of Invasive Ductal and Lobular Breast Carcinomas: A Systematic Review and Meta-analysis. Clinical breast cancer, 2020. 20(4): p. e516–e528.32362500
58 Dinu, M., , Vegetarian, vegan diets and multiple health outcomes: A systematic review with meta-analysis of observational studies. Critical reviews in food science and nutrition, 2017. 57(17): p. 3640–3649.26853923
59 Dinu, M., , Mediterranean diet and multiple health outcomes: An umbrella review of meta-analyses of observational studies and randomized trials. Nutrition, Metabolism & Cardiovascular Diseases, 2017. 27(1): p. e21–e21.
60 Dominguez, L.J., , Rationale of the association between Mediterranean diet and the risk of frailty in older adults and systematic review and meta-analysis. Experimental gerontology, 2023. 177: p. 112180.37087024
61 Du, H., , Mediterranean Diet Patterns in Relation to Lung Cancer Risk: A Meta-Analysis. Frontiers in nutrition, 2022. 9: p. 844382.35495942
62 Du, M., , Associations between Diet Quality Scores and Risk of Postmenopausal Estrogen Receptor-Negative Breast Cancer: A Systematic Review. The Journal of nutrition, 2018. 148(1): p. 100–108.29378048
63 Du, S., , Index-based dietary patterns in relation to gastric cancer risk: a systematic review and meta-analysis. The British journal of nutrition, 2020. 123(9): p. 964–974.31767045
64 Eleftheriou, D., , Mediterranean diet and its components in relation to all-cause mortality: meta-analysis. The British journal of nutrition, 2018. 120(10): p. 1081–1097.30401007
65 Esgunoglu, L., , Short-term effects of a Mediterranean-style dietary pattern on cognition and mental well-being: a systematic review of clinical trials. The British journal of nutrition, 2022. 128(7): p. 1247–1256.34236017
66 Eslami, O., M. Zarei, and F. Shidfar, The association of dietary patterns and cardiorespiratory fitness: A systematic review. Nutrition, metabolism, and cardiovascular diseases : NMCD, 2020. 30(9): p. 1442–1451.32513576
67 Esposito, K., , Dietary factors, Mediterranean diet and erectile dysfunction. The journal of sexual medicine, 2010. 7(7): p. 2338–45.20487239
68 Esposito, K., , Mediterranean diet and metabolic syndrome: an updated systematic review. Reviews in endocrine & metabolic disorders, 2013. 14(3): p. 255–63.23982678
69 Farsinejad-Marj, M., , Adherence to Mediterranean diet and risk of breast cancer in premenopausal and postmenopausal women. Archives of Iranian medicine, 2015. 18(11): p. 786–92.26497377
70 Fazelian, S., , Adherence to the vegetarian diet may increase the risk of depression: a systematic review and meta-analysis of observational studies. Nutrition reviews, 2022. 80(2): p. 242–254.33822140
71 Feiertag, N., , Should Men Eat More Plants? A Systematic Review of the Literature on the Effect of Plant-Forward Diets on Men's Health. Urology, 2023. 176: p. 7–15.36963667
72 Feldman, E., Mediterranean Diet and Frailty Risk...Kojima G, Avgerinou C, Iliffe S, Walters K. Adherence to Mediterranean diet reduces incident frailty risk: Systematic review and meta-analysis. J Am Geriatr Soc 2018; Jan. 11. Integrative Medicine Alert, 2018. 21(4): p. 37–40.
73 Field, R., , Dietary Interventions Are Beneficial for Patients with Chronic Pain: A Systematic Review with Meta-Analysis. Pain medicine (Malden, Mass.), 2021. 22(3): p. 694–714.33202007
74 Filippou, C., , PS-C09–2: EFFECT OF DIETARY APPROACHES TO STOP HYPERTENSION OR MEDITERRANEAN DIET ON BLOOD PRESSURE IN ADULTS: A SYSTEMATIC REVIEW AND META-ANALYSIS. Journal of Hypertension, 2023. 41: p. e207–e207.
75 Forsyth, C., , The effects of the Mediterranean diet on rheumatoid arthritis prevention and treatment: a systematic review of human prospective studies. Rheumatology international, 2018. 38(5): p. 737–747.29256100
76 Fu, J., , Association between the mediterranean diet and cognitive health among healthy adults: A systematic review and meta-analysis. Frontiers in nutrition, 2022. 9: p. 946361.35967772
77 Garbett, T.M., D.L. Garbett, and A. Wendorf, Vegetarian Diet: A Prescription for High Blood Pressure? A Systematic Review of the Literature. Journal for Nurse Practitioners, 2016. 12(7): p. 452–458.
78 Garcia-Casares, N., , Alzheimer's Disease, Mild Cognitive Impairment and Mediterranean Diet. A Systematic Review and Dose-Response Meta-Analysis. Journal of clinical medicine, 2021. 10(20).
79 Gastaldello, A., , Adherence to the Mediterranean-Style Eating Pattern and Macular Degeneration: A Systematic Review of Observational Studies. Nutrients, 2022. 14(10).
80 Gay, H.C., , Effects of Different Dietary Interventions on Blood Pressure: Systematic Review and Meta-Analysis of Randomized Controlled Trials. Hypertension (Dallas, Tex. : 1979), 2016. 67(4): p. 733–9.26902492
81 George, E.S., , The Association between Diet and Hepatocellular Carcinoma: A Systematic Review. Nutrients, 2021. 13(1).
82 Ghadimi, M., , Effectiveness of dietary interventions on cardio-metabolic risk factors in patients with nonalcoholic fatty liver disease: a systematic review and meta-analysis of randomized controlled trials. Annals of gastroenterology, 2021. 34(3): p. 415–423.33948068
83 Godos, J., , Dietary patterns and risk of colorectal adenoma: a systematic review and meta-analysis of observational studies. Journal of human nutrition and dietetics : the official journal of the British Dietetic Association, 2016. 29(6): p. 757–767.27412573
84 Gonzalez-Palacios Torres, C., , Mediterranean diet and risk of breast cancer: An umbrella review. Clinical nutrition (Edinburgh, Scotland), 2023. 42(4): p. 600–608.36893621
85 Gosal, H., , The Significance of the Mediterranean Diet in the Management of Non-Alcoholic Fatty Liver Disease: A Systematic Review. Cureus, 2021. 13(6): p. e15618.34277236
86 Gregory, S., , Mediterranean diet and structural neuroimaging biomarkers of Alzheimer's and cerebrovascular disease: A systematic review. Experimental gerontology, 2023. 172: p. 112065.36529364
87 Grisotto, G., , Dietary factors and onset of natural menopause: A systematic review and meta-analysis. Maturitas, 2022. 159: p. 15–32.35337609
88 Gupta, N., , Systematic review of the impact of a plant-based diet on prostate cancer incidence and outcomes. Prostate cancer and prostatic diseases, 2022. 25(3): p. 444–452.35790788
89 Gutierrez, L., , Effects of Nutrition on Cognitive Function in Adults with or without Cognitive Impairment: A Systematic Review of Randomized Controlled Clinical Trials. Nutrients, 2021. 13(11).
90 Guzek, D., , Fruit and Vegetable Dietary Patterns and Mental Health in Women: A Systematic Review. Nutrition reviews, 2022. 80(6): p. 1357–1370.34041545
91 Hadefi, A., , Dietary strategies in non-alcoholic fatty liver disease patients: From evidence to daily clinical practice, a systematic review. United European gastroenterology journal, 2023. 11(7): p. 663–689.37491835
92 Hagen, K.B., , Dietary interventions for rheumatoid arthritis. The Cochrane database of systematic reviews, 2009(1): p. CD006400.19160281
93 Haigh, L., , The effectiveness and acceptability of Mediterranean diet and calorie restriction in non-alcoholic fatty liver disease (NAFLD): A systematic review and meta-analysis. Clinical nutrition (Edinburgh, Scotland), 2022. 41(9): p. 1913–1931.35947894
94 Hansrivijit, P., , Mediterranean diet and the risk of chronic kidney disease: A systematic review and meta-analysis. Nephrology (Carlton, Vic.), 2020. 25(12): p. 913–918.32852121
95 Hassani Zadeh, S., A. Mansoori, and M. Hosseinzadeh, Relationship between dietary patterns and non-alcoholic fatty liver disease: A systematic review and meta-analysis. Journal of gastroenterology and hepatology, 2021. 36(6): p. 1470–1478.33269500
96 Hersant, H. and G. Grossberg, The Ketogenic Diet and Alzheimer's Disease. Journal of Nutrition, Health & Aging, 2022. 26(6): p. 606–614.
97 Ho-Pham, L.T., N.D. Nguyen, and T.V. Nguyen, Effect of vegetarian diets on bone mineral density: a Bayesian meta-analysis. The American journal of clinical nutrition, 2009. 90(4): p. 943–50.19571226
98 Holton, K.F., L.L. Kindler, and K.D. Jones, Potential dietary links to central sensitization in fibromyalgia: past reports and future directions. Rheumatic Disease Clinics of North America, 2009. 35(2): p. 409–420.19647151
99 Houttu, V., , Dietary Interventions in Patients With Non-alcoholic Fatty Liver Disease: A Systematic Review and Meta-Analysis. Frontiers in nutrition, 2021. 8: p. 716783.34368214
100 Huang, L., , Mediterranean-Dietary Approaches to Stop Hypertension Intervention for Neurodegenerative Delay (MIND) Diet and Cognitive Function and its Decline: A Prospective Study and Meta-analysis of Cohort Studies. The American journal of clinical nutrition, 2023. 118(1): p. 174–182.37105521
101 Iguacel, I., , Vegetarianism and veganism compared with mental health and cognitive outcomes: a systematic review and meta-analysis. Nutrition reviews, 2021. 79(4): p. 361–381.32483598
102 Iguacel, I., , Veganism, vegetarianism, bone mineral density, and fracture risk: a systematic review and meta-analysis. Nutrition reviews, 2019. 77(1): p. 1–18.30376075
103 Jaber, M., , Mediterranean diet diminishes the effects of Crohn's disease and improves its parameters: A systematic review. Nutrition and health, 2022: p. 2601060221102281.35611526
104 Jain, R., , Association between vegetarian and vegan diets and depression: A systematic review. Nutrition bulletin, 2022. 47(1): p. 27–49.36045075
105 Jang, E.-H., , Association between Diet Quality and Sarcopenia in Older Adults: Systematic Review of Prospective Cohort Studies. Life (Basel, Switzerland), 2021. 11(8).
106 Kawaguchi, T., , Effects of Mediterranean Diet in Patients with Nonalcoholic Fatty Liver Disease: A Systematic Review, Meta-Analysis, and Meta-Regression Analysis of Randomized Controlled Trials. Seminars in liver disease, 2021. 41(3): p. 225–234.34147036
107 Khaled, K., , Perceived stress and diet quality in women of reproductive age: a systematic review and meta-analysis. Nutrition journal, 2020. 19(1): p. 92.32859204
108 Kheirouri, S. and M. Alizadeh, MIND diet and cognitive performance in older adults: a systematic review. Critical reviews in food science and nutrition, 2022. 62(29): p. 8059–8077.33989093
109 Kim, J., , The synergistic effect of physical activity and nutrition to improve the quality of life in breast cancer patients: a systemic review. Physical activity and nutrition, 2022. 26(4): p. 22–31.
110 Klimova, B., , The Effect of Mediterranean Diet on Cognitive Functions in the Elderly Population. Nutrients, 2021. 13(6): p. 2067–2067.34208741
111 Klímová, B. and M. Vališ, Nutritional Interventions as Beneficial Strategies to Delay Cognitive Decline in Healthy Older Individuals. Nutrients, 2018. 10(7): p. 1–10.
112 Knight, A., J. Bryan, and K. Murphy, The Mediterranean diet and age-related cognitive functioning: A systematic review of study findings and neuropsychological assessment methodology. Nutritional neuroscience, 2017. 20(8): p. 449–468.27192034
113 Kojima, G., , Adherence to Mediterranean Diet Reduces Incident Frailty Risk: Systematic Review and Meta-Analysis. Journal of the American Geriatrics Society, 2018. 66(4): p. 783–788.29322507
114 Kontou, N., , The Mediterranean Diet in Cancer Prevention: A Review. Journal of Medicinal Food, 2011. 14(10): p. 1065–1078.21663480
115 Kouvari, M., , Metabolic Syndrome, Cognitive Impairment and the Role of Diet: A Narrative Review. Nutrients, 2022. 14(2): p. 333–333.35057514
116 Kunutsor, S.K., , Adherence to a Mediterranean-style diet and incident fractures: pooled analysis of observational evidence. European journal of nutrition, 2018. 57(4): p. 1687–1700.28331983
117 Langhorst, J., , [Alternative and complementary therapies in fibromyalgia syndrome]. Komplementare und alternative Verfahren beim Fibromyalgiesyndrom., 2008. 22(3): p. 324–33.
118 Lassale, C., , Healthy dietary indices and risk of depressive outcomes: a systematic review and meta-analysis of observational studies. Molecular psychiatry, 2019. 24(7): p. 965–986.30254236
119 Leno-Duran, E., , [Influence of diet in COVID-19 infection and severity risk: a systematic review]. Influencia de la dieta en el riesgo de infeccion y de gravedad de la COVID-19: una revision sistematica., 2023. 40(2): p. 444–456.
120 Li, S., , Effects of the Dietary Approaches to Stop Hypertension (DASH) on Pregnancy/Neonatal Outcomes and Maternal Glycemic Control: A Systematic Review and Meta-analysis of Randomized Clinical Trials. Complementary therapies in medicine, 2020. 54: p. 102551.33183669
121 Limongi, F., , The Effect of Adherence to the Mediterranean Diet on Late-Life Cognitive Disorders: A Systematic Review. Journal of the American Medical Directors Association, 2020. 21(10): p. 1402–1409.32981667
122 Lin, B.-B., , Dietary and lifestyle factors for primary prevention of nephrolithiasis: a systematic review and meta-analysis. BMC nephrology, 2020. 21(1): p. 267.32652950
123 Liu, K.Q., X.Y. Ding, and W.H. Zhao, [Influence of dietary pattern on human immunity]. Zhonghua yi xue za zhi, 2020. 100(48): p. 3890–3896.33371637
124 Lopez, P.D., , The Effect of Vegan Diets on Blood Pressure in Adults: A Meta-Analysis of Randomized Controlled Trials. The American journal of medicine, 2019. 132(7): p. 875–883.e7.30851264
125 López-Guarnido, O., , Mediterranean diet adherence and prostate cancer risk. Nutrición Hospitalaria, 2015. 31(3): p. 1012–1019.
126 Loughrey, D.G., , The Impact of the Mediterranean Diet on the Cognitive Functioning of Healthy Older Adults: A Systematic Review and Meta-Analysis. Advances in nutrition (Bethesda, Md.), 2017. 8(4): p. 571–586.28710144
127 Lourida, I., , Mediterranean diet, cognitive function, and dementia: a systematic review. Epidemiology (Cambridge, Mass.), 2013. 24(4): p. 479–89.23680940
128 Lowry, E., , Dietary Interventions in the Management of Fibromyalgia: A Systematic Review and Best-Evidence Synthesis. Nutrients, 2020. 12(9).
129 Lv, N., L. Xiao, and J. Ma, Dietary pattern and asthma: a systematic review and meta-analysis. Journal of asthma and allergy, 2014. 7: p. 105–21.25143747
130 Ma, X., , The impact of plant-based diets on female bone mineral density: Evidence based on seventeen studies. Medicine, 2021. 100(46): p. e27480.34797275
131 Madani, S., , The relationship between the Mediterranean diet and Axis I disorders: A systematic review of observational studies. Food science & nutrition, 2022. 10(10): p. 3241–3258.36249971
132 Maddox, E.K., , Dietary Effects on Pain Symptoms in Patients with Fibromyalgia Syndrome: Systematic Review and Future Directions. Nutrients, 2023. 15(3).
133 Malmir, H., , Adherence to Mediterranean diet in relation to bone mineral density and risk of fracture: a systematic review and meta-analysis of observational studies. European journal of nutrition, 2018. 57(6): p. 2147–2160.28638994
134 Mann, S., M. Sidhu, and K. Gowin, Understanding the Mechanisms of Diet and Outcomes in Colon, Prostate, and Breast Cancer; Malignant Gliomas; and Cancer Patients on Immunotherapy. Nutrients, 2020. 12(8): p. 2226.32722632
135 Manta, E., , EFFECT OF DIETARY APPROACHES TO STOP HYPERTENSION DIET OR MEDITERRANEAN DIET ON BLOOD PRESSURE IN INDIVIDUALS WITH OR WITHOUT HYPERTENSION: A SYSTEMATIC REVIEW AND META-ANALYSIS. Journal of Hypertension, 2022. 40: p. e263–e263.
136 Masana, M.F., , n-3 Fatty acids, Mediterranean diet and cognitive function in normal aging: A systematic review. Experimental gerontology, 2017. 91: p. 39–50.28213052
137 Mascaro, C.M., C. Bouzas, and J.A. Tur, Association between Non-Alcoholic Fatty Liver Disease and Mediterranean Lifestyle: A Systematic Review. Nutrients, 2021. 14(1).
138 Mathieu, S., E. Hanras, and G. Dorard, Associations between vegetarianism, body mass index, and eating disorders/disordered eating behaviours: a systematic review of literature. International journal of food sciences and nutrition, 2023. 74(4): p. 424–462.37431146
139 Matison, A.P., , Associations between nutrition and the incidence of depression in middle-aged and older adults: A systematic review and meta-analysis of prospective observational population-based studies. Ageing research reviews, 2021. 70: p. 101403.34246793
140 McBean, L. and S. O'Reilly, Diet quality interventions to prevent neurocognitive decline: a systematic review and meta-analysis. European journal of clinical nutrition, 2022. 76(8): p. 1060–1072.34732834
141 McEvoy, C.T., , Interventions involving a major dietary component improve cognitive function in cognitively healthy adults: a systematic review and meta-analysis. Nutrition research (New York, N.Y.), 2019. 66: p. 1–12.31022563
142 McKeown, P.P., , Session 4: CVD, diabetes and cancer: evidence for the use of the Mediterranean diet in patients with CHD. Proceedings of the Nutrition Society, 2010. 69(1): p. 45–60.20003638
143 Medawar, E., , The effects of plant-based diets on the body and the brain: a systematic review. Translational psychiatry, 2019. 9(1): p. 226.31515473
144 Milajerdi, A., , The Association of Dietary Quality Indices and Cancer Mortality: A Systematic Review and Meta-analysis of Cohort Studies. Nutrition and cancer, 2018. 70(7): p. 1091–1105.30321058
145 Miller, P.E., , Dietary patterns and colorectal adenoma and cancer risk: a review of the epidemiological evidence. Nutrition & Cancer, 2010. 62(4): p. 413–424.20432162
146 Mohseni, R., , The Association of Dietary Approaches to Stop Hypertension (DASH) Diet with the Risk of Colorectal Cancer: A Meta-Analysis of Observational Studies. Nutrition and cancer, 2020. 72(5): p. 778–790.31418286
147 Molina-Montes, E., , The Impact of Plant-Based Dietary Patterns on Cancer-Related Outcomes: A Rapid Review and Meta-Analysis. Nutrients, 2020. 12(7).
148 Moosavian, S.P., A. Arab, and Z. Paknahad, The effect of a Mediterranean diet on metabolic parameters in patients with non-alcoholic fatty liver disease: A systematic review of randomized controlled trials. Clinical nutrition ESPEN, 2020. 35: p. 40–46.31987120
149 Morales-Ivorra, I., , Osteoarthritis and the Mediterranean Diet: A Systematic Review. Nutrients, 2018. 10(8).
150 Mozaffari, H., S. Ajabshir, and S. Alizadeh, Dietary Approaches to Stop Hypertension and risk of chronic kidney disease: A systematic review and meta-analysis of observational studies. Clinical nutrition (Edinburgh, Scotland), 2020. 39(7): p. 2035–2044.31669002
151 Muffone, A.R.M.C., P.D.P. de Oliveira Lubke, and E.I. Rabito, Mediterranean diet and infertility: a systematic review with meta-analysis of cohort studies. Nutrition reviews, 2023. 81(7): p. 775–789.36346903
152 Muller, H., F.W. de Toledo, and K.L. Resch, Fasting followed by vegetarian diet in patients with rheumatoid arthritis: a systematic review. Scandinavian journal of rheumatology, 2001. 30(1): p. 1–10.11252685
153 Nadal-Nicolas, Y., , Vegetarian and Vegan Diet in Fibromyalgia: A Systematic Review. International journal of environmental research and public health, 2021. 18(9).
154 Ndanuko, R.N., , Dietary Patterns and Blood Pressure in Adults: A Systematic Review and Meta-Analysis of Randomized Controlled Trials. Advances in nutrition (Bethesda, Md.), 2016. 7(1): p. 76–89.26773016
155 Nissensohn, M., , The Effect of the Mediterranean Diet on Hypertension: A Systematic Review and Meta-Analysis. Journal of nutrition education and behavior, 2016. 48(1): p. 42–53.e1.26483006
156 Niu, Y., , Effects of a vegetarian diet combined with exercise on lipid profiles and blood pressure: A systematic review and meta-analysis. Critical reviews in food science and nutrition, 2022: p. 1–15.
157 Noori, M., , Mediterranean dietary pattern and bone mineral density: a systematic review and dose-response meta-analysis of observational studies. European journal of clinical nutrition, 2022. 76(12): p. 1657–1664.35173291
158 Nosrati-Oskouie, M., , Current evidence on dietary factors and kidney allograft function in kidney transplant recipients: a systematic review. Current medicinal chemistry, 2023.
159 Nucci, D., , Adherence to Mediterranean Diet and Risk of Pancreatic Cancer: Systematic Review and Meta-Analysis. International journal of environmental research and public health, 2023. 20(3).
160 Nurmatov, U., G. Devereux, and A. Sheikh, Nutrients and foods for the primary prevention of asthma and allergy: systematic review and meta-analysis. The Journal of allergy and clinical immunology, 2011. 127(3): p. 724–30.21185068
161 Ocklenburg, S. and J. Borawski, Vegetarian diet and depression scores: A meta-analysis. Journal of affective disorders, 2021. 294: p. 813–815.34375207
162 Onvani, S., F. Haghighatdoost, and L. Azadbakht, Dietary approach to stop hypertension (DASH): diet components may be related to lower prevalence of different kinds of cancer: A review on the related documents. Journal of Research in Medical Sciences, 2015. 20(7): p. 707–713.26622263
163 Ortolan, A., , The impact of diet on disease activity in spondyloarthritis: A systematic literature review. Joint bone spine, 2023. 90(2): p. 105476.36404571
164 Otaegui-Arrazola, A., , Diet, cognition, and Alzheimer's disease: food for thought. European Journal of Nutrition, 2014. 53(1): p. 1–23.
165 Oussalah, A., , Health outcomes associated with vegetarian diets: An umbrella review of systematic reviews and meta-analyses. Clinical nutrition (Edinburgh, Scotland), 2020. 39(11): p. 3283–3307.32204974
166 Papadaki, A., E. Nolen-Doerr, and C.S. Mantzoros, The Effect of the Mediterranean Diet on Metabolic Health: A Systematic Review and Meta-Analysis of Controlled Trials in Adults. Nutrients, 2020. 12(11).
167 Papadopoulou, S.K., , Mediterranean Diet and Sarcopenia Features in Apparently Healthy Adults over 65 Years: A Systematic Review. Nutrients, 2023. 15(5).
168 Parohan, M., , Dietary total antioxidant capacity and mortality from all causes, cardiovascular disease and cancer: a systematic review and dose–response meta-analysis of prospective cohort studies. European Journal of Nutrition, 2019. 58(6): p. 2175–2189.30756144
169 Parra-Soto, S., , Association of meat, vegetarian, pescatarian and fish-poultry diets with risk of 19 cancer sites and all cancer: findings from the UK Biobank prospective cohort study and meta-analysis. BMC medicine, 2022. 20(1): p. 79.35655214
170 Petersson, S.D. and E. Philippou, Mediterranean Diet, Cognitive Function, and Dementia: A Systematic Review of the Evidence. Advances in nutrition (Bethesda, Md.), 2016. 7(5): p. 889–904.27633105
171 Philippou, E., , Rheumatoid arthritis and dietary interventions: systematic review of clinical trials. Nutrition reviews, 2021. 79(4): p. 410–428.32585000
172 Pourmasoumi, M., , Healthy Eating Index/Alternative Healthy Eating Index and Breast Cancer Mortality and Survival: A Systematic Review and Meta-analysis. Asia-Pacific Journal of Oncology Nursing, 2016. 3(3): p. 297–305.27981174
173 Pratistita, P.T.P. and M.B. Marbun, THE ROLE OF DIETARY APPROACHES TO STOP HYPERTENSION (DASH DIET) ON BLOOD PRESSURE IN PATIENTS WITH HYPERTENSION. Journal of Hypertension, 2022. 40: p. e262–e262.
174 Proietti, A.R., , [Mediterranean diet and prevention of non-communicable diseases: scientific evidences]. La dieta Mediterranea nella prevenzione delle patologie cronico-degenerative: evidenze scientifiche., 2009. 21(3): p. 197–210.
175 Psaltopoulou, T., , Mediterranean diet, stroke, cognitive impairment, and depression: A meta-analysis. Annals of neurology, 2013. 74(4): p. 580–91.23720230
176 Radd-Vagenas, S., , Effect of the Mediterranean diet on cognition and brain morphology and function: a systematic review of randomized controlled trials. The American journal of clinical nutrition, 2018. 107(3): p. 389–404.29566197
177 Rahe, C., M. Unrath, and K. Berger, Dietary patterns and the risk of depression in adults: a systematic review of observational studies. European Journal of Nutrition, 2014. 53(4): p. 997–1013.24468939
178 Rahmati, M., , The effect of adherence to high-quality dietary pattern on COVID-19 outcomes: A systematic review and meta-analysis. Journal of medical virology, 2023. 95(1): p. e28298.36367218
179 Reddy, A.J., , Effect of dietary intervention, with or without co-interventions, on inflammatory markers in patients with nonalcoholic fatty liver disease: a systematic literature review. Nutrition reviews, 2019. 77(11): p. 765–786.31361003
180 Rinninella, E., , Nutritional Interventions to Improve Clinical Outcomes in Ovarian Cancer: A Systematic Review of Randomized Controlled Trials. Nutrients, 2019. 11(6): p. 1404.31234395
181 Rokou, A., , Effect of the Implementation of a Structured Diet Management Plan on the Severity of Obstructive Sleep Apnea: A Systematic Review. Current nutrition reports, 2023. 12(1): p. 26–38.36435894
182 Romero Pérez, A. and A. Rivas Velasco, Adherence to Mediterranean diet and bone health. Nutrición Hospitalaria, 2014. 29(5): p. 989–996.24951976
183 Rudzinska, A., , Can the Mediterranean diet decrease the risk of depression in older persons - a systematic review. Czy dieta srodziemnomorska moze zmniejszac ryzyko depresji u osob w starszym wieku - przeglad systematyczny pismiennictwa., 2023. 57(2): p. 339–354.
184 Saeed, N., , Evaluation of Dietary Approaches for the Treatment of Non-Alcoholic Fatty Liver Disease: A Systematic Review. Nutrients, 2019. 11(12).
185 Samadi, M., , Dietary pattern in relation to the risk of Alzheimer's disease: a systematic review. Neurological sciences : official journal of the Italian Neurological Society and of the Italian Society of Clinical Neurophysiology, 2019. 40(10): p. 2031–2043.31240575
186 Sanchez-Sanchez, M.L., , Mediterranean diet and health: A systematic review of epidemiological studies and intervention trials. Maturitas, 2020. 136: p. 25–37.32386663
187 Saneei, P., , Influence of Dietary Approaches to Stop Hypertension (DASH) diet on blood pressure: a systematic review and meta-analysis on randomized controlled trials. Nutrition, metabolism, and cardiovascular diseases : NMCD, 2014. 24(12): p. 1253–61.25149893
188 Schwingshackl, L., B. Bogensberger, and G. Hoffmann, Diet Quality as Assessed by the Healthy Eating Index, Alternate Healthy Eating Index, Dietary Approaches to Stop Hypertension Score, and Health Outcomes: An Updated Systematic Review and Meta-Analysis of Cohort Studies. Journal of the Academy of Nutrition and Dietetics, 2018. 118(1): p. 74–100.e11.29111090
189 Schwingshackl, L. and G. Hoffmann, Mediterranean dietary pattern, inflammation and endothelial function: a systematic review and meta-analysis of intervention trials. Nutrition, metabolism, and cardiovascular diseases : NMCD, 2014. 24(9): p. 929–39.24787907
190 Schwingshackl, L. and G. Hoffmann, Adherence to Mediterranean diet and risk of cancer: a systematic review and meta-analysis of observational studies. International journal of cancer, 2014. 135(8): p. 1884–97.24599882
191 Schwingshackl, L. and G. Hoffmann, Adherence to Mediterranean diet and risk of cancer: an updated systematic review and meta-analysis of observational studies. Cancer medicine, 2015. 4(12): p. 1933–47.26471010
192 Schwingshackl, L., , Adherence to Mediterranean Diet and Risk of Cancer: An Updated Systematic Review and Meta-Analysis. Nutrients, 2017. 9(10).
193 Senderovich, H., O. Farahneh, and S. Waicus, The Role of Intermittent Fasting and Dieting on Cognition in Adult Population: A Systematic Review of the Randomized Controlled Trials. Medical principles and practice : international journal of the Kuwait University, Health Science Centre, 2023. 32(2): p. 99–109.37263255
194 Serra-Majem, L., B. Roman, and R. Estruch, Scientific evidence of interventions using the Mediterranean diet: a systematic review. Nutrition reviews, 2006. 64(2 Pt 2): p. S27–47.16532897
195 Shafiei, F., , Adherence to the Mediterranean diet and risk of depression: a systematic review and updated meta-analysis of observational studies. Nutrition reviews, 2019. 77(4): p. 230–239.30726966
196 Shafiei, F., , Mediterranean diet and depression: reanalysis of a meta-analysis. Nutrition reviews, 2023. 81(7): p. 889–890.36928725
197 Shah, R., The role of nutrition and diet in Alzheimer disease: a systematic review. Journal of the American Medical Directors Association, 2013. 14(6): p. 398–402.23419980
198 Shannon, O.M., , Mediterranean Diet Increases Endothelial Function in Adults: A Systematic Review and Meta-Analysis of Randomized Controlled Trials. The Journal of nutrition, 2020. 150(5): p. 1151–1159.32027740
199 Shu, L., , Adherence to the Dietary Approaches to Stop Hypertension diet reduces the risk of breast cancer: A systematic review and meta-analysis. Frontiers in nutrition, 2022. 9: p. 1032654.36698472
200 Siervo, M., , Effects of the Dietary Approach to Stop Hypertension (DASH) diet on cardiovascular risk factors: a systematic review and meta-analysis. The British journal of nutrition, 2015. 113(1): p. 1–15.25430608
201 Silva, A.R., , Dietary interventions in fibromyalgia: a systematic review. Annals of medicine, 2019. 51(sup1): p. 2–14.30735059
202 Silva, R., , Mediterranean Diet and Musculoskeletal-Functional Outcomes in Community-Dwelling Older People: A Systematic Review and Meta-Analysis. The journal of nutrition, health & aging, 2018. 22(6): p. 655–663.
203 Singh, B., , Association of mediterranean diet with mild cognitive impairment and Alzheimer's disease: a systematic review and meta-analysis. Journal of Alzheimer's disease : JAD, 2014. 39(2): p. 271–82.24164735
204 Smedslund, G., , Effectiveness and safety of dietary interventions for rheumatoid arthritis: a systematic review of randomized controlled trials. Journal of the American Dietetic Association, 2010. 110(5): p. 727–35.20430134
205 Smits, K.P.J., S. Listl, and M. Jevdjevic, Vegetarian diet and its possible influence on dental health: A systematic literature review. Community dentistry and oral epidemiology, 2020. 48(1): p. 7–13.31571246
206 Sofi, F., , Mediterranean diet and health status: an updated meta-analysis and a proposal for a literature-based adherence score. Public health nutrition, 2014. 17(12): p. 2769–82.24476641
207 Solch, R.J., , Mediterranean diet adherence, gut microbiota, and Alzheimer's or Parkinson's disease risk: A systematic review. Journal of the neurological sciences, 2022. 434: p. 120166.35144237
208 Solfrizzi, V., , Relationships of Dietary Patterns, Foods, and Micro- and Macronutrients with Alzheimer's Disease and Late-Life Cognitive Disorders: A Systematic Review. Journal of Alzheimer's disease : JAD, 2017. 59(3): p. 815–849.28697569
209 Stamp, L.K., M.J. James, and L.G. Cleland, Diet and rheumatoid arthritis: a review of the literature. Seminars in Arthritis & Rheumatism, 2005. 35(2): p. 77–94.16194694
210 Steck, S.E., , Index-based dietary patterns and colorectal cancer risk: a systematic review. Advances in nutrition (Bethesda, Md.), 2015. 6(6): p. 763–73.26567200
211 Swainson, J., , Diet and depression: A systematic review of whole dietary interventions as treatment in patients with depression. Journal of affective disorders, 2023. 327: p. 270–278.36738997
212 Swiatek, L., , The impact of a vegetarian diet on chronic kidney disease (CKD) progression - a systematic review. BMC nephrology, 2023. 24(1): p. 168.37308813
213 Syed Soffian, S.S., , Meta-Analysis of the Association between Dietary Inflammatory Index (DII) and Colorectal Cancer. Nutrients, 2022. 14(8): p. N.PAG-N.PAG.
214 Taghavi, M., , Adherence to the dietary approaches to stop hypertension-style diet is inversely associated with chronic kidney disease: a systematic review and meta-analysis of prospective cohort studies. Nutrition research (New York, N.Y.), 2019. 72: p. 46–56.31740009
215 Tan, J., C. Wang, and A.J. Tomiyama, Dietary Approaches to Stop Hypertension (DASH) diet and mental well-being: a systematic review. Nutrition reviews, 2023.
216 Tangestani, H., , Adherence to the Dietary Approaches to Stop Hypertension (DASH) dietary pattern reduces the risk of colorectal cancer: A systematic review and meta-analysis. Clinical nutrition (Edinburgh, Scotland), 2020. 39(10): p. 2975–2981.32063407
217 Tian, Z., , Index-Based Dietary Patterns and Inflammatory Bowel Disease: A Systematic Review of Observational Studies. Advances in nutrition (Bethesda, Md.), 2021. 12(6): p. 2288–2300.34157069
218 Tolkien, K., S. Bradburn, and C. Murgatroyd, An anti-inflammatory diet as a potential intervention for depressive disorders: A systematic review and meta-analysis. Clinical nutrition (Edinburgh, Scotland), 2019. 38(5): p. 2045–2052.30502975
219 Tome-Carneiro, J. and F. Visioli, Plant-Based Diets Reduce Blood Pressure: A Systematic Review of Recent Evidence. Current hypertension reports, 2023. 25(7): p. 127–150.37178356
220 Townsend, R.F., , Whole Dietary Patterns, Cognitive Decline and Cognitive Disorders: A Systematic Review of Prospective and Intervention Studies. Nutrients, 2023. 15(2).
221 Ubago-Guisado, E., , Evidence Update on the Relationship between Diet and the Most Common Cancers from the European Prospective Investigation into Cancer and Nutrition (EPIC) Study: A Systematic Review. Nutrients, 2021. 13(10).
222 Vahid, F. and D. Rahmani, Can an anti-inflammatory diet be effective in preventing or treating viral respiratory diseases? A systematic narrative review. Clinical nutrition ESPEN, 2021. 43: p. 9–15.34024569
223 Vajdi, M. and M.A. Farhangi, A systematic review of the association between dietary patterns and health-related quality of life. Health and quality of life outcomes, 2020. 18(1): p. 337.33046091
224 van Brakel, L., , Nutritional Interventions to Improve Asthma-Related Outcomes through Immunomodulation: A Systematic Review. Nutrients, 2020. 12(12): p. 3839.33339167
225 van de Rest, O., , Dietary patterns, cognitive decline, and dementia: a systematic review. Advances in nutrition (Bethesda, Md.), 2015. 6(2): p. 154–68.25770254
226 van den Brandt, P.A. and M. Schulpen, Mediterranean diet adherence and risk of postmenopausal breast cancer: results of a cohort study and meta-analysis. International journal of cancer, 2017. 140(10): p. 2220–2231.28260236
227 van den Brink, A.C., , The Mediterranean, Dietary Approaches to Stop Hypertension (DASH), and Mediterranean-DASH Intervention for Neurodegenerative Delay (MIND) Diets Are Associated with Less Cognitive Decline and a Lower Risk of Alzheimer's Disease-A Review. Advances in nutrition (Bethesda, Md.), 2019. 10(6): p. 1040–1065.31209456
228 Verberne, L., , Association Between the Mediterranean Diet and Cancer Risk: A Review of Observational Studies. Nutrition & Cancer, 2010. 62(7): p. 860–870.20924961
229 Wang, J., , Dietary inflammatory index and depression: a meta-analysis. Public health nutrition, 2018: p. 1–7.29227217
230 Wang, S., , Benefits of Dietary Management in Breast Cancer Patients: A Systematic Review and Meta-Analysis. Nutrition & Cancer, 2022. 74(5): p. 1580–1592.34319187
231 Wang, Y., , Adherence to the Mediterranean Diet and the Risk of Frailty in Old People: A Systematic Review and Meta-Analysis. The journal of nutrition, health & aging, 2018. 22(5): p. 613–618.
232 Watts, S.A., C. Stevenson, and J. Patterson, What does the evidence say about the Mediterranean diet? Nursing, 2018. 48(3): p. 50–54.
233 Weber, I., J. Giefer, and K.L. Martin, Effects of Exercise and Dietary Modifications on Hidradenitis Suppurativa: A Systematic Review. American journal of clinical dermatology, 2023. 24(3): p. 343–357.36757580
234 Weigl, J., H. Hauner, and D. Hauner, Can Nutrition Lower the Risk of Recurrence in Breast Cancer? Breast Care, 2018. 13(2): p. 86–91.29887784
235 Wu, L. and D. Sun, Adherence to Mediterranean diet and risk of developing cognitive disorders: An updated systematic review and meta-analysis of prospective cohort studies. Scientific reports, 2017. 7: p. 41317.28112268
236 Wu, Y., , The Mediterranean Diet and Age-Related Eye Diseases: A Systematic Review. Nutrients, 2023. 15(9).
237 Xu, C., , Role of dietary patterns and factors in determining the risk of knee osteoarthritis: A meta-analysis. Modern rheumatology, 2022. 32(4): p. 815–821.34918108
238 Xu Lou, I., K. Ali, and Q. Chen, Effect of nutrition in Alzheimer's disease: A systematic review. Frontiers in neuroscience, 2023. 17: p. 1147177.37214392
239 Xu Lou, I., , Nutritional aspects in chronic non-cancer pain: A systematic review. Frontiers in nutrition, 2022. 9: p. 931090.36003834
240 Yang, J., , Dietary Inflammatory Index and Ovarian Cancer Risk: A Meta-Analysis. Nutrition & Cancer, 2022. 74(3): p. 796–805.34060392
241 Yokoyama, Y., , Vegetarian diets and blood pressure: a meta-analysis. JAMA internal medicine, 2014. 174(4): p. 577–87.24566947
242 Yusufov, M., L.L. Weyandt, and I. Piryatinsky, Alzheimer's disease and diet: a systematic review. The International journal of neuroscience, 2017. 127(2): p. 161–175.26887612
243 Zaragoza-Marti, A., , Adherence to the Mediterranean Diet in Pregnancy and Its Benefits on Maternal-Fetal Health: A Systematic Review of the Literature. Frontiers in nutrition, 2022. 9: p. 813942.35433794
244 Zhang, M., , Dietary and Lifestyle Factors Related to Gastroesophageal Reflux Disease: A Systematic Review. Therapeutics and clinical risk management, 2021. 17: p. 305–323.33883899
245 Zhang, Y.-H., Z. Li, and M.-Z. Tan, Association Between Diet Quality and Risk of Ovarian and Endometrial Cancers: A Systematic Review of Epidemiological Studies. Frontiers in oncology, 2021. 11: p. 659183.34084748
246 Zhao, L., , Dietary Patterns and Risk of Lung Cancer: A Systematic Review and Meta-Analyses of Observational Studies. Current nutrition reports, 2023. 12(2): p. 338–357.37097371
247 Zhao, Y., , The Relationship Between Plant-Based Diet and Risk of Digestive System Cancers: A Meta-Analysis Based on 3,059,009 Subjects. Frontiers in public health, 2022. 10: p. 892153.35719615
248 Zhong, Y., , Association between Mediterranean diet adherence and colorectal cancer: a dose-response meta-analysis. The American journal of clinical nutrition, 2020. 111(6): p. 1214–1225.32359135
249 Zmerly, H., , Personalized Nutritional Strategies to Reduce Knee Osteoarthritis Severity and Ameliorate Sarcopenic Obesity Indices: A Practical Guide in an Orthopedic Setting. Nutrients, 2023. 15(14): p. 3085.37513503
250 Μεταξούλη, Κ. and Ν. Μάργαρη, ΜΕΣΟΓΕΙΑΚΗ ΔΙΑΤΡΟΦΗ ΚΑΙ ΝΕΥΡΟΛΟΓΙΚΑ ΝΟΣΗ-ΜΑΤΑ. Perioperative Nursing, 2022. 11(3): p. 236–244.
251 이건아, 최혜영, and 양숙자, 대사증후군에 대한 식이와 운동 효과에 대한 메타분석. Journal of Korean Academy of Nursing, 2015. 45(4): p. 483–494.26364523

### Topic CVD, N = 22

1 Amati, F., S. Hassounah, and A. Swaka, The Impact of Mediterranean Dietary Patterns During Pregnancy on Maternal and Offspring Health. Nutrients, 2019. 11(5).
2 Boushey, C., , Dietary Patterns and All-Cause Mortality: A Systematic Review. 2020.
3 Carvalho, C.M.d., , Dietary Fiber Intake (Supplemental or Dietary Pattern Rich in Fiber) and Diabetic Kidney Disease: A Systematic Review of Clinical Trials. Nutrients, 2019. 11(2).
4 Chen, G.-C., , Adherence to the Mediterranean diet and risk of stroke and stroke subtypes. European journal of epidemiology, 2019. 34(4): p. 337–349.30826941
5 Doundoulakis, I., , Effects of dietary interventions on cardiovascular outcomes: a network meta-analysis. Nutrition reviews, 2023.
6 E, L., Healthy eating and mortality among breast cancer survivors: A systematic review and meta-analysis of cohort studies. Breast Cancer Research Review, 2022(38): p. 4–4.
7 Genel, F., , Health effects of a low-inflammatory diet in adults with arthritis: a systematic review and meta-analysis. Journal of nutritional science, 2020. 9: p. e37.32983422
8 Huo, R., , Effects of Mediterranean-style diet on glycemic control, weight loss and cardiovascular risk factors among type 2 diabetes individuals: a meta-analysis. European journal of clinical nutrition, 2015. 69(11): p. 1200–8.25369829
9 Karam, G., , Comparison of seven popular structured dietary programmes and risk of mortality and major cardiovascular events in patients at increased cardiovascular risk: systematic review and network meta-analysis. BMJ (Clinical research ed.), 2023. 380: p. e072003.
10 Kwok, C.S., , Vegetarian diet, Seventh Day Adventists and risk of cardiovascular mortality: a systematic review and meta-analysis. International journal of cardiology, 2014. 176(3): p. 680–6.25149402
11 Lu, J.-W., , Risk of Incident Stroke among Vegetarians Compared to Nonvegetarians: A Systematic Review and Meta-Analysis of Prospective Cohort Studies. Nutrients, 2021. 13(9).
12 Netting, M.J., P.F. Middleton, and M. Makrides, Does maternal diet during pregnancy and lactation affect outcomes in offspring? A systematic review of food-based approaches. Nutrition (Burbank, Los Angeles County, Calif.), 2014. 30(11–12): p. 1225–41.25280403
13 Palmer, S.C., , Dietary interventions for adults with chronic kidney disease. The Cochrane database of systematic reviews, 2017. 4: p. CD011998.28434208
14 Picasso, M.C., , Effect of vegetarian diets on the presentation of metabolic syndrome or its components: A systematic review and meta-analysis. Clinical nutrition (Edinburgh, Scotland), 2019. 38(3): p. 1117–1132.29907356
15 Rees, K., , Mediterranean-style diet for the primary and secondary prevention of cardiovascular disease. The Cochrane database of systematic reviews, 2019. 3: p. CD009825.30864165
16 Sanches Machado d'Almeida, K., , Mediterranean Diet and Other Dietary Patterns in Primary Prevention of Heart Failure and Changes in Cardiac Function Markers: A Systematic Review. Nutrients, 2018. 10(1).
17 Sanchez-Rosales, A.I., , The Effect of Dietary Patterns on Inflammatory Biomarkers in Adults with Type 2 Diabetes Mellitus: A Systematic Review and Meta-Analysis of Randomized Controlled Trials. Nutrients, 2022. 14(21).
18 Saulle, R., , A systematic overview of the scientific literature on the association between Mediterranean Diet and the Stroke prevention. La Clinica terapeutica, 2019. 170(5): p. e396–e408.31612199
19 Soltani, S. and A. Jayedi, Adherence to healthy dietary pattern and risk of kidney disease: a systematic review and meta-analysis of observational studies. International journal for vitamin and nutrition research. Internationale Zeitschrift fur Vitamin- und Ernahrungsforschung. Journal international de vitaminologie et de nutrition, 2022. 92(3–4): p. 267–279.32138628
20 Tan, C., Y. Zhao, and S. Wang, Is a vegetarian diet safe to follow during pregnancy? A systematic review and meta-analysis of observational studies. Critical reviews in food science and nutrition, 2019. 59(16): p. 2586–2596.29621406
21 Wang, X., , Effects of various interventions on non-alcoholic fatty liver disease (NAFLD): A systematic review and network meta-analysis. Frontiers in pharmacology, 2023. 14: p. 1180016.37063273
22 Zeng, J., , The effects of dietary patterns and food groups on symptomatic osteoarthritis: A systematic review. Nutrition & dietetics: the journal of the Dietitians Association of Australia, 2023. 80(1): p. 21–43.36278278

### Study Design, N = 19

1 Andrews, V., G. Zammit, and F. OĽeary, Dietary pattern, food, and nutritional supplement effects on cognitive outcomes in mild cognitive impairment: a systematic review of previous reviews. Nutrition reviews, 2023.
2 Barbaresko, J., , Dietary Factors and Neurodegenerative Disorders: An Umbrella Review of Meta-Analyses of Prospective Studies. Advances in nutrition (Bethesda, Md.), 2020. 11(5): p. 1161–1173.32427314
3 Brlek, A. and M. Gregoric, Diet quality indices and their associations with all-cause mortality, CVD and type 2 diabetes mellitus: an umbrella review. The British journal of nutrition, 2023. 130(4): p. 709–718.36423897
4 Buckinx, F. and M. Aubertin-Leheudre, Nutrition to Prevent or Treat Cognitive Impairment in Older Adults: A GRADE Recommendation. The journal of prevention of Alzheimer's disease, 2021. 8(1): p. 110–116.
5 De Pergola, G. and A. D'Alessandro, Influence of Mediterranean Diet on Blood Pressure. Nutrients, 2018. 10(11).
6 Dinu, M., , Mediterranean diet and multiple health outcomes: an umbrella review of meta-analyses of observational studies and randomised trials. European journal of clinical nutrition, 2018. 72(1): p. 30–43.28488692
7 Galbete, C., , Evaluating Mediterranean diet and risk of chronic disease in cohort studies: an umbrella review of meta-analyses. European journal of epidemiology, 2018. 33(10): p. 909–931.30030684
8 Gianfredi, V., , Association between dietary patterns and depression: an umbrella review of meta-analyses of observational studies and intervention trials. Nutrition reviews, 2023. 81(3): p. 346–359.36240456
9 Gianfredi, V., , Diets, Dietary Patterns, Single Foods and Pancreatic Cancer Risk: An Umbrella Review of Meta-Analyses. International journal of environmental research and public health, 2022. 19(22).
10 Lockwood, C., Dietary interventions for adults with chronic kidney disease: A Cochrane review summary. International Journal of Nursing Studies, 2018. 88: p. 163–164.29519588
11 Marshall, T.A., Weak Evidence Suggests Vegetarian Diets May Be Associated With an Increased Risk of Dental Erosion. The journal of evidence-based dental practice, 2021. 21(1): p. 101524.34051953
12 Martinez-Lacoba, R., , Mediterranean diet and health outcomes: a systematic meta-review. European journal of public health, 2018. 28(5): p. 955–961.29992229
13 Nicolaou, M., , Association of a priori dietary patterns with depressive symptoms: a harmonised meta-analysis of observational studies. Psychological medicine, 2020. 50(11): p. 1872–1883.31409435
14 Pameijer, E.M., , What did we learn in 35 years of research on nutrition and supplements for age-related macular degeneration: a systematic review. Acta ophthalmologica, 2022. 100(8): p. e1541–e1552.35695158
15 Porras, M., G. Rada, and J. Duran, Effects of Mediterranean diet on the treatment of rheumatoid arthritis. Efectos de la dieta mediterranea en el tratamiento de la artritis reumatoide., 2019. 19(5): p. e7640.
16 Qin, X., , Dietary Factors and Pancreatic Cancer Risk: An Umbrella Review of Meta-Analyses of Prospective Observational Studies. Advances in nutrition (Bethesda, Md.), 2023. 14(3): p. 451–464.36849084
17 Simoes Correa Galendi, J., , Effectiveness of Strategies for Nutritional Therapy for Patients with Type 2 Diabetes and/or Hypertension in Primary Care: A Systematic Review and Meta-Analysis. International journal of environmental research and public health, 2022. 19(7).
18 Smith, A.M., Veganism and osteoporosis: a review of the current literature. International Journal of Nursing Practice (Wiley-Blackwell), 2006. 12(5): p. 302–306.
19 Sukhato, K., , Efficacy of different dietary patterns on lowering of blood pressure level: an umbrella review. The American journal of clinical nutrition, 2020. 112(6): p. 1584–1598.33022695

## PEER REVIEW COMMENTS AND RESPONSES

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 2 | No - The rationale for examining the specific dietary patterns in this paper was not well documented. In addition, this is largely described as an evidence map - though in some placed referred to as an umbrella review - and clarity to type of evidence synthesis product and alignment with the methods would be helpful. | We have added a description of the rationale for the choice of dietary patterns we included.
2 | 3 | Yes | N/A
3 | 4 | Yes | N/A
4 | 5 | Yes | N/A
5 | 6 | Yes | N/A
6 | 7 | Yes | N/A
7 | 8 | Yes | N/A
Is there any indication of bias in our synthesis of the evidence?
8 | 2 | No | N/A
9 | 3 | No | N/A
10 | 4 | No | N/A
11 | 5 | No | N/A
12 | 6 | No | N/A
13 | 7 | No | N/A
14 | 8 | No | N/A
Are there any published or unpublished studies that we may have overlooked?
15 | 2 | No | N/A
16 | 3 | Diet and Chronic Non-Cancer Pain: The State of the Art and Future Directions. Authors: Brain, K et. al. published 2021 | We reviewed this publication, but it did not meet inclusion criteria as it is not a systematic review.
17 | 3 | Dietary recommendations for the prevention of depression. Author: Opie et. al Published 2017 | We reviewed this publication, but it did not meet inclusion criteria as it is not a systematic review.
18 | 3 | Effect of polyphenols in a Mediterranean diet on symptoms of depression: A systematic literature review. Authors: Bayes, J et. al. | We reviewed this publication, but it did not meet inclusion criteria as it about specific nutrients, and not diets of interest.
19 | 4 | No | N/A
20 | 5 | No | N/A
21 | 6 | No | N/A
22 | 7 | No | N/A
23 | 8 | No | N/A
Additional suggestions or comments can be provided below.
General
24 | 3 | I believe including the WHO definition of the clinical term “frailty” under evidenced maps where frailty is discussed (page 13) would be beneficial to clinicians who are not familiar. Frailty is an important factor in health and aging; and the clinical usefulness of reducing this risk would be a helpful acknowledgement in the report. Clinicians who are not familiar with the term may not understand the full impact of reducing its occurrence. | Added as text to the first results section that mentions frailty.
25 | 4 | It may helpful to further emphasize the fact that studies on cardiovascular disease, diabetes, and obesity were omitted due to the assumption that it is widely accepted that anti-inflammatory diets are beneficial for prevention and treatment of these conditions. There is a wide body of evidence supporting this, and Mediterranean diets are recommended by the American Diabetes Association, American Heart Association, and Academy of Nutrition and Dietetics for these conditions. In order to make the body of evidence more manageable for an evidence map, we chose to exclude CVD, diabetes, and obesity and to focus on other conditions that have not been studied quite as much. This evidence makes it quite clear, that more high quality research is needed on anti-inflammatory diets, especially for cancer, liver disease, and frailty. | Added a version of this language to the executive summary
26 | 4 | Another challenge highlighted by this evidence map, is the difficulty defining an anti-inflammatory eating pattern; the definition of anti-inflammatory eating pattern is not consistent across all studies, which makes it difficult to compare the effects. For example, DASH diets and Mediterranean Diets both promote increased fruits, vegetables, whole grains, legumes, and nuts and seeds; however, the Mediterranean Diet includes additional anti-inflammatory properties such as olive oil, fish, and herbs and spices. Studies that focus specifically on anti-inflammatory diets, such as those that use the DII are so limited without any RCTs that it is hard to draw conclusions. | Added language to both the inclusion criteria table and the conclusions (limitations) to address this.
27 | 5 | I would not suggest including DASH diet. DASH diet may not always fall in the category of an anti-inflammatory plan. | We included DASH because it shares many of the anti-inflammatory properties endorsed by other diets, and when discussed during scoping conversations with our operations partners and technical experts, the group reached consensus to include it.
28 | 6 | Please add IFNCP to the credentials for Kwynn Mason | Added IFNCP for Kwynn Mason.
29 | 8 | Overall, great, thorough review. I was surprised there were no findings related to things like depression, anxiety, fibromyalgia, chronic fatigue, etc. I did a preliminary search for SRs related to these conditions and then found that the SRs I came across were listed under excluded studies. It might be helpful to include in the background or study selection sections some mention of these other conditions for which no findings are reported because the studies didn’t meet inclusion criteria. | We added a statement to the limitations that addresses this point.
Executive Summary
30 | 2 | Page ii: I am a strong proponent of including the librarian or bioinformaticist that developed and execute the literature search as an author on the paper, rather than just mentioning their role in the acknowledgements. Developing a comprehensive literature search is fundamental to the review process, and I believe that role warrants authorship. | We often do include librarians as co-authors. For this project specifically, the librarian we worked with was unavailable during the drafting and report development, and as such we were unable to include her in the process and could not get her permission to be included as an author.
31 | 2 | Page v, Key Findings: Given that this is an evidence map, and not a review of reviews or umbrella review, making recommendations on the basis of the findings may not be warranted. Recommendations should be based on a review, in which the risk of bias or quality of studies is evaluated, evidence is synthesized, and strength of evidence assessed. | We agree making recommendations on the effectiveness or efficacy of anti-inflammatory diets based on evidence maps would be inappropriate. We have revised the wording to clarify that our recommendations pertain to the strength of evidence, quality of existing literature, and gaps in the literature.
32 | 8 | 1) Pg v, lines 4–5 under Key Findings, 1st bullet point, 2nd statement uses studies/study 3 times. | Reworded
33 | 8 | 2) Pg v, line 8 – shouldn’t “blood pressure” here be “high blood pressure” or “hypertension”? | Reworded
34 | 8 | 3) Pg v, lines 9–10 – suggest changing “However, these observations could be due to foods excluded from these dietary patterns or to foods they include” to something like “The observed benefits could be related to the exclusion of particular foods from the dietary patterns, the inclusion of particular foods, or both.” | Reworded
35 | 8 | 4) Pg v, lines 10 – I’m not sure I agree that there is a “lack of understanding of how anti-inflammatory diets might be beneficial for preventing and managing some chronic conditions.” It is fairly well-established that inflammation plays an underlying role in many chronic conditions, as are the mechanisms by which various dietary compounds influence the synthesis of anti-inflammatory or pro-inflammatory cytokines. -- Edited to add that language on pg 4 “Proposed mechanisms and direct evidence are generally lacking. Whether inflammation is a cause or consequence of various disease processes remains unclear” is more clear. | We have reworded the language in this section.
36 | 8 | 5) Pg v, lines 32–33 – beginning of this sentence needs rewording (see pg vi, line 2–4). | Reworded
37 | 3 | Page vi, line 14 down. Would be helpful to have all 18 moderately supported conclusions listed in one place instead of just a few. Either here or later on in the report. | The conclusions with high certainty of evidence are listed in the summary; We could create a table of the moderate CoE conclusions but given that this is an evidence map, we would hesitate to give them that much weight.
38 | 8 | 6) Pg viii, lines 7–9 – same as comment #1 above regarding repetitious use of the word studies/study. | We revised the sentence.
39 | 8 | 7) Pg viii, line 15–17 – same as # 4 above: I’m not sure I agree that there is a “lack of understanding of how anti-inflammatory diets might be beneficial for preventing and managing some chronic conditions.” It is fairly well-established that inflammation plays an underlying role in many chronic conditions, as are the mechanisms by which various dietary compounds influence the synthesis of anti-inflammatory or pro-inflammatory cytokines. -- Edited to add that language on pg 4 “Proposed mechanisms and direct evidence are generally lacking. Whether inflammation is a cause or consequence of various disease processes remains unclear” is more clear. | We revised the wording, as indicated above.
40 | 8 | 8) Pg viii, line 18 – Delete “Limitations” prior to “This evidence map has a number of limitations...” | We deleted “Limitations” and included transitional words for clarity.
41 | 8 | 9) Pg ix, line 18 – RE: “immutable factors such as genetics” – doesn’t seem to account for reality that genes don’t exist in a vacuum and diet affects gene expression (nutrigenomics). | Revised
42 | 8 | 10) Pg ix, line 24 – same as #2 above: shouldn’t “blood pressure” her be “high blood pressure” or “hypertension”? | Revised
43 | 4 | Page ix, lines 20–26: The first two conclusions that were supported by high certainty of evidence seem very similar and could maybe be combined into one? The relationship between DASH diet and HTN is widely accepted; summarizing these two conclusions may give more clout to the others listed. | These conclusions are separated because one is based on a review of patients with hypertension, and the other was based on studies of people with normal BP or pre-hypertension.
Introduction
44 | 2 | Pg 4, introduction: The introduction is not adequately referenced. Numerous statements are made with no supporting citations provided. | Additional references have been added to the introduction.
45 | 8 | 11) Pg 4, line 10 – dietitian (as opposed to dietician) was adopted as the official spelling in 1930. | Spelling changed throughout the document.
46 | 3 | Page 4, line 10. Dietitians is generally spelled with a T and to remain consistent in the publication would recommend changing “dieticians” to dietitians | Spelling changed throughout the document.
47 | 2 | Pg 4, after Line 16: Consider adding a section to introduce “nutrition and inflammation.” The introduction addresses inflammation and health, and diet and chronic disease, but does not adequately set the stage for the relationship between diet and inflammation. | We cited at least one recent review on the evidence linking nutrition and inflammation, but since the purpose of this report is to compile the evidence linking nutrition and inflammation, we would not ordinarily do this.
48 | 2 | Pg 4, line 33: It would be helpful to establishing the scope and purpose of this work to provide a definition of inflammation. | We have added this definition and elaborated on the link between chronic inflammation and disease.
49 | 2 | Pg 5, Lines 5–7: While DASH is relatively lower in refined carbs and saturated fat, those are not the defining features of DASH – rather fruits, vegetables, lean meats, low-fat dairy, and lower sodium are. This sentence does not adequately define or describe the key features of the DASH pattern. | We greatly expanded on the description of the DASH diet.
50 | 8 | 12) Pg 5, line 5–7 – while it is true that the DASH diet is low in refined carbs and sat fat, it is specifically characterized as being high in fruits, vegetables, nuts, whole grains, and low-fat dairy and emphasizing fish, chicken and lean meats as animal protein sources. | We have augmented the description of DASH.
51 | 2 | Pg 5, Line 23–25: I am unaware of any Mediterranean diet score that includes level of processing as a scoring feature. As with DASH, the Mediterranean diet is not defined on the basis of animal fats or simple carbohydrates – but rather fruits, vegetables, olive oil, lean meat and seafood, etc. This is an inadequate description of the pattern. | We have significantly modified this description with additional references.
Methods
52 | 2 | Page 6, Line 13: Here, this work is referred to as an umbrella review – whereas elsewhere its referred to as an evidence map. Those are fundamentally different products – with an umbrella review more often thought of as a systematic review of reviews that seeks to draw and grade conclusions from the evidence, and an evidence map as the result of scoping activity intended to describe what has been published on a topic – more descriptive in nature. | We have made the language consistent.
53 | 2 | Pages 7–8, Eligibility criteria: This table would be easier for the reader to follow if it included separate columns for inclusion and exclusion criteria. As currently presented, its hard to easily sort through what is in and what is out. | This table is the standard format for our products.
54 | 2 | Page 7, Lines 7–23: The authors have indicated an interest in focusing on a small set of specific dietary patterns, but have not provide clear rationale or justification for focusing on these patterns. Suggest adding content to the introduction and/or methods to provide justification. | We added text to the introduction elaborating on the rationale. We were asked to focus on these diets by the sponsor, with whom we worked to focus on the most relevant outcomes and dietary patterns.
55 | 2 | Page 7, Lines 25–27: Recommend making note that only reviews that included formal evidence grading somewhere in the executive summary. | We have added that to the description of study selection.
56 | 8 | 13) Pg 8, first bullet– wondering why DASH low sodium was excluded? | DASH Low Sodium studies were excluded because studies of that diet combined the DASH diet (which is similar in important ways to other anti-inflammatory diets) with a low-sodium focused diet. Therefore, it would not be possible to attribute findings solely to the anti-inflammatory aspects of the eating pattern without considering the possible synergism with lower sodium/higher potassium intake.
57 | 2 | Page 8: While this is an evidence map, it seems the authors were interested in taking it a step further – and using the information gathered to provide practitioners with recommendations. Thus, it is not clear why the quality or risk of bias of the identified reviews was not assessed using AMSTAR or the ROBIS tool. This assessment would help in interpreting and describing the reviews in the maps and help better inform recommendations. However, if this remains an evidence map, and not an umbrella review, this assessment may not be needed. | The report was in fact intended to be an evidence map. Also, by imposing the inclusion criterion of GRADE or other certainty of evidence assessment, we assessed a higher quality subset of existing systematic reviews. Further, our intention was not to provide recommendations but to simply map the evidence and expose gaps.
58 | 2 | Pg 9, Synthesis: Were any efforts made to evaluate the overlap in primary articles in reviews addressing the same dietary patterns and outcomes? Without this assessment, later in the paper, one cannot simply add the total included articles to estimate what evidence has been published on a topic. Also, without evaluating this overlap, its difficult to determine whether reviews on the same topic are based on the same or different bodies of evidence. | We now describe areas of overlap wherever possible. There were instances where we were unable to determine overlap based on the way included reviews reported on their data, but in all cases where there was overlap observed, we now include this in the text.
59 | 2 | Pg 9, Synthesis, Line 1: Given that this is an evidence map, using the term “synthesis” to describe this step of the process may be inappropriate. Rather, the authors should describe this as “description of the evidence.” | The Synthesis section describes the approaches taken to understand the identified evidence. This general usage of “synthesis” is well established in the systematic review context, where the term encompasses quantitative pooling of studies as well as visualization and narrative synthesis methods like those used in the present review.
60 | 8 | 14) Pg 9, lines 5–6: says information is displayed on 4 dimensions but then names 5. | It is actually 5. Thank you.
Results
61 | 2 | Pg 11, Lines 6–7: use of the term “cardiovascular disease topic” is confusing here, given that reviews on CVD were excluded. Recommend changing this to more directly refer to BP? | This term is used to describe the number of studies excluded for covering that topic, but we have clarified that BP studies were included.
62 | 2 | Pg 11, Characteristics of Included Reviews: Consider describing the outcomes addressed in the review first and the types of dietary patterns examined before describing the number of conclusions drawn. Also, does the number of conclusions matter as much as the nature or direction and strength of the conclusions. That may not be a very useful metric to report. This is also where you can describe the 2 patterns – other than DASH and MD – that are covered in the evidence map. | Because this is an evidence map, the numbers of conclusions per review and their crosswalk is simply an introduction to describing the landscape and mapping.
63 | 8 | 15) Pg 11, Characteristics of Included Reviews -- the number of reviews for each diet doesn’t seem to match what is stated in the exec summary, pg vi, lines 39–40 & pg vii, lines 1–2 | The information reported in the Executive Summary (numbers of reviews that reported on each dietary pattern) is different from the information reported in the main report. We have added the information from the Summary to the main report.
64 | 8 | 16) Pg 11 – delete “Error! Reference source not found.” | We don’t see that. It may have appeared in the pdf that was sent out for review. We apologize.
65 | 3 | Pg 11, has the following sentence that needs to be removed. “Error! Reference source not found.” | We don’t see that. It may have appeared in the pdf that was sent out for review. We apologize.
66 | 2 | Pg 11, Lines 19–22: These sentences seem out of place, and would be better paired with the previous content about the number of conclusions drawn. | We have reorganized the sentences to clarify the descriptions.
67 | 5 | I would also consider an evidence map for the anti-inflammatory research listed on page 12. | We are not sure what the reviewer is referring to. If the suggestion is to create an evidence map for the reviews of anti-inflammatory research identical to figure 4, the map in the Executive Summary is intended only as a sample.
68 | 2 | Pg 13, Evidence Maps: A lot of the content in this section directly reports identical content to that in the actual figures or tables. In addition, throughout this section, the Tables are not internally referenced in the text. In all of the sections in this section, the information is not reported in a consistent format. It would be most useful to begin each section by orienting the reader the number of reviews identified, describing their findings, and sharing the conclusions and strength of evidence grades. In some cases, the grade or conclusion is mentioned before the reader has a sense for what was found in the literature. | We have reorganized the text to be more consistent across conditions and diets. We also added callouts for the figures and tables and information on the various ways of assessing the Med diet.
69 | 2 | Pg 13, Evidence Maps: It would be very useful for the authors to provide a more thorough discussion and description of how the dietary patterns were defined in the literature – including how they were measured, the similar and dissimilar food and beverage components across papers, etc. | We have added a discussion of the definitions and the various measures used to assess the Mediterranean diet.
70 | 2 | Pg 13, Lines 11–12: Multiple measures of what? Multiple measures of dietary intake over time? Or multiple MD scoring indices? | The latter: we have completely revised the wording to clarify that multiple different tools were used to assess the MD.
71 | 2 | Pg 13, Blood Pressure: This section is a good example of where one wonders how much overlap there is in the primary studies included in all of the reviews addressing the same topic. | We now report on the overlap between studies included in the two reviews of RCTs for MD and BP and discuss this in greater detail in our response to comment 58.
72 | 2 | Pg 14, Lines 18–20: For a mapping activity, it seems highly useful to provide more documentation on these low and very low certainty reviews. I would suggest adding them into the main report, and not leaving them to a supplement only. This can be critical information for practitioners – who are likely interested in knowing where the evidence is strong, but also where there is no or very weak evidence. | A challenge is that for some conditions (eg, cancer and frailty for the Mediterranean Diet) some reviews reported moderate-to-high certainty conclusions while others reported low or very low certainly conclusions for the same conditions. We also have added an explanation regarding why we do not describe conclusions with low or very low certainty of evidence in the narrative.
73 | 2 | Pg 15, Figure 2 (all figures): These are very helpful figures overall, but there is a lot of blank space – and some of the text is hard to read. The term “mixed” is also not clear – I presume this means both trials and observational studies? I would recommend just directly stating that in all places where “mixed” is used in this report. Also, these figures need to be able to standalone – and would benefit from more description labels/titles, keys, etc. | We have added the description of the symbols to the introductory text in the Results section. Since there were categories for which we found no studies, we are not sure how to rebalance the space.
74 | 2 | Pg 16, Table 2: This table would be more useful to the reader if the studies were grouped by outcome, rather than alphabetical. The table would better support the text if re-organized in that way. | We agree and have done so.
75 | 2 | Pg 23, DII & Pg 26 Vegetarian/Plantbased: These sections seems to be missing the same kind of introductory paragraph provided for MD and DASH. In addition, the term “plant-based” is problematic – while it commonly used by lay people, its really unclear from a scientific perspective, and it would be better to just use the term vegetarian, if that’s the case. (Most people consume a “plant-based” diet, given that the majority if the average person’s diet comes from plant foods, including grains.) | We have added explanatory paragraphs regarding the DII and vegetarian diets.
76 | 2 | Pg 26: Consider describing the vegan dietary pattern evidence within this section. | We have re-organized the diet sections so that the vegan diet section immediately follows the vegetarian/plant-based diet section.
77 | 5 | For the evidence maps, adding in the type of cancers would be helpful. For example, on page 24, Figure 4. Since these dietary approaches are similar, could we look at some of similarities and look at overall impact and build an evidence map off of those similarities? | The tables of conclusions report the types of cancer and we have added that information to the text. We believe adding that information to the evidence maps would make them unreadable.
78 | 2 | Pg 34, Discussion: Did the authors consider including a more in-depth discussion of the commonalities between the DASH and MD dietary patterns, and how those relate or compare to current dietary guidance? Using only labels to describe dietary patterns is not always the most useful to practitioners or the public. It would be very useful to describe the common foods and beverages and highlight how much similarity there is between those patterns. When the commonalities are taken into account, it would seem that there is actually quite a bit of evidence, high and moderate strength, to support the recommendation of dietary patterns with fruits, vegetables, lean meats and seafood, low-fat dairy for a host of chronic conditions. | We have added this information to the introduction and we now briefly review it again in the Discussion.
79 | 2 | Pg 34, Lines 17–18: Please see my previous comment about this not being an appropriate characterization of the key features of the DASH diet. | We have completely revised our description of the DASH diet.
80 | 8 | 17) Pg 34, lines 17–18 – again, reducing the DASH diet to “a diet low in saturated fat” misses the defining characteristics as mentioned in #12 above. | We have added detail regarding the DASH diet to the introduction as well as to the Discussion.
81 | 2 | Pg 35, Table 8: This is a nice table, but it would be nice to see the same for the moderate reviews. Many are willing to base recommendations or guidance on high or moderate strength evidence, and highlighting all of that evidence would be useful to the end-user. | We have added a table with moderate reviews after table 8.
82 | 2 | Pg 36: The number of search results is not an acceptable way to assess publication bias. Rather, you should focus on the comprehensive literature search that was done across multiple databases with no time restrictions. | Yes, we did not intend for these numbers to serve as evidence of the inclusiveness of our searches. We have omitted the statements
83 | 2 | Pg 36: You cannot make a statement about the number of primary studies without evaluating overlap between reviews. | Yes, we have now assessed overlap of included studies where two or more reviews reported on the same intervention/exposure and outcomes, but we also deleted the comment regarding numbers of studies.
84 | 2 | Pg 36, Lines 38–39: This limitation could easily be addressed by doing an AMSTAR assessment of each review. | We chose to use the criterion of conducting an assessment of the certainty of evidence in lieu of conducting AMSTAR or ROBINS.
85 | 2 | Pg 36, Line 30: Please provide more information about what criteria was used to determine what review was “the most informative.” | We now have listed our criteria.
86 | 2 | Pg 36: Confounding is indeed an issue - but theoretically the grading accounted for this. So, while it is certainly a limitation of the primary literature - it seems unfair to make such a strong statement about it here, given that it is taken into consideration during the grading process, and the grades assigned account for it. In addition, the authors have not appropriately recognized the limitations of trials in this type of literature. Dietary patterns are intended to be consumed over time – and many of the outcomes are long-term – meaning that RCTs, especially short-term ones, cannot adequately capture the exposure and outcomes of interest. | We reframed the discussion of this limitation in light of your observations.
87 | 2 | Pg 37, Conclusions: Based on the evidence identified, and the number of high and moderate reviews identified, I am not sure I would agree that the evidence is sparse? The evidence available was consistent, particularly when consider the commonalities between many of the patterns examined. | We have reframed this sentence.
88 | 8 | Pg 38, line 4 – the Keys Seven Countries Study was not published in 2024, and the link listed is not a link to the actual study itself. | We thought it would be more helpful to cite a recent perspective on the importance of that study but have replaced it with one of the original references.