# ABBREVIATIONS TABLE

Abbreviation: Definition
AHRQ: Agency for Healthcare Research & Quality
AMED: Alternate mediterranean diet
BP: Blood pressure
CRC: Colorectal cancer
DAS28: Disease activity score in 28 joints
DASH: Dietary Approaches to Stop Hypertension
DBP: Diastolic blood pressure
DGA: Dietary Guidelines for Americans
DGC: Dietary Guidelines Committee
Dll: Dietary Inflammatory Index
DRIs: Dietary Reference Intakes
EPC: Evidence-based Practice Center
ESP: Evidence Synthesis Program
GRADE: Grading of Recommendations, Assessment, Development and Evaluations
HCC: Hepatocellular carcinoma
MD: Mediterranean diet
MDS: Mediterranean Diet Score
MEDAS: Mediterranean Diet Adherence Screener
MIND: Mediterranean-Dietary Approaches to Stop Hypertension Intervention for Neurodegenerative Delay
MSDPS: Mediterranean-style Dietary Pattern Score
NAFLD: Nonalcoholic fatty liver disease
SBP: Systolic blood pressure
SR: Systematic review
TEP: Technical Expert Panel
UGI: Upper gastrointestinal
VA: Veterans Affairs
VHA: Veterans Health Administration