# REFERENCES

1 Lange KW, Reichl S, Lange KM, Tucha L, Tucha O. The history of attention deficit hyperactivity disorder. Atten Defic Hyperact Disord. Dec 2010;2(4):241–55. doi:10.1007/s12402-010-0045-8 21258430
2 Witrick B, Zhang D, Su D, . Medical Expenditures Associated with Attention-Deficit/Hyperactivity Disorder Among Adults in the United States by Age, 2015-2019. J Gen Intern Med. Jul 2023;38(9):2082–2090. doi:10.1007/s11606-023-08075-w 36781580
3 Austerman J. ADHD and behavioral disorders: Assessment, management, and an update from DSM-5. Cleve Clin J Med. Nov 2015;82(11 Suppl 1):S2–7. doi:10.3949/ccjm.82.s1.01 26555810
4 Cortese S, Coghill D. Twenty years of research on attention-deficit/hyperactivity disorder (ADHD): looking back, looking forward. Evid Based Ment Health. Nov 2018;21(4):173–176. doi:10.1136/ebmental-2018-300050 30301823
5 Barkley RA, Fischer M, Smallish L, Fletcher K. Young adult outcome of hyperactive children: adaptive functioning in major life activities. J Am Acad Child Adolesc Psychiatry. Feb 2006;45(2):192–202. doi:10.1097/01.chi.0000189134.97436.e2 16429090
6 Rohner H, Gaspar N, Philipsen A, Schulze M. Prevalence of Attention Deficit Hyperactivity Disorder (ADHD) among Substance Use Disorder (SUD) Populations: Meta-Analysis. Int J Environ Res Public Health. Jan 10 2023;20(2)doi:10.3390/ijerph20021275
7 Sibley MH, Mitchell JT, Becker SP. Method of adult diagnosis influences estimated persistence of childhood ADHD: a systematic review of longitudinal studies. Lancet Psychiatry. Dec 2016;3(12):1157–1165. doi:10.1016/s2215-0366(16)30190-0 27745869
8 Fairman KA, Peckham AM, Sclar DA. Diagnosis and Treatment of ADHD in the United States: Update by Gender and Race. J Atten Disord. Jan 2020;24(1):10–19. doi:10.1177/1087054716688534 28152660
9 Kessler RC, Adler L, Barkley R, . The prevalence and correlates of adult ADHD in the United States: results from the National Comorbidity Survey Replication. Am J Psychiatry. Apr 2006;163(4):716–23. doi:10.1176/ajp.2006.163.4.716 16585449
10 Chung W, Jiang SF, Paksarian D, . Trends in the Prevalence and Incidence of Attention-Deficit/Hyperactivity Disorder Among Adults and Children of Different Racial and Ethnic Groups. JAMA Netw Open. Nov 1 2019;2(11):e1914344. doi:10.1001/jamanetworkopen.2019.14344 31675080
11 1 Medical Standards for Military Service: Appointment, Enlistment, or Induction (2018).
12 Hale AC, Bohnert KM, Spencer RJ, Ganoczy D, Pfeiffer PN. The Prevalence and Incidence of Attention-deficit/Hyperactivity Disorder in the Veterans Health Administration From 2009 to 2016. Med Care. Mar 2020;58(3):273–279. doi:10.1097/mlr.0000000000001287 32049948
13 Sayers D, Hu Z, Clark LL. Attrition Rates and Incidence of Mental Health Disorders in an Attention-Deficit/Hyperactivity Disorder (ADHD) Cohort, Active Component, U.S. Armed Forces, 2014-2018. Msmr. Jan 2021;28(1):2–8.
14 Sayers D, Hu Z, Clark LL. The Prevalence of Attention-Deficit/Hyperactivity Disorder (ADHD) and ADHD Medication Treatment in Active Component Service Members, U.S. Armed Forces, 2014-2018. Msmr. Jan 2021;28(1):9–14.
15 Cecil CAM, Nigg JT. Epigenetics and ADHD: Reflections on Current Knowledge, Research Priorities and Translational Potential. Mol Diagn Ther. Nov 2022;26(6):581–606. doi:10.1007/s40291-022-00609-y 35933504
16 Luo Y, Weibman D, Halperin JM, Li X. A Review of Heterogeneity in Attention Deficit/Hyperactivity Disorder (ADHD). Front Hum Neurosci. 2019;13:42. doi:10.3389/fnhum.2019.00042 30804772
17 Norman LJ, Carlisi C, Lukito S, . Structural and Functional Brain Abnormalities in Attention-Deficit/Hyperactivity Disorder and Obsessive-Compulsive Disorder: A Comparative Meta-analysis. JAMA Psychiatry. Aug 1 2016;73(8):815–825. doi:10.1001/jamapsychiatry.2016.0700 27276220
18 Véronneau-Veilleux F, Robaey P, Ursino M, Nekka F. A mechanistic model of ADHD as resulting from dopamine phasic/tonic imbalance during reinforcement learning. Front Comput Neurosci. 2022;16:849323. doi:10.3389/fncom.2022.849323 35923915
19 Bokor G, Anderson PD. Attention-Deficit/Hyperactivity Disorder. J Pharm Pract. Aug 2014;27(4):336–49. doi:10.1177/0897190014543628 25092688
20 Adamou M, Arif M, Asherson P, . Occupational issues of adults with ADHD. BMC Psychiatry. Feb 17 2013;13:59. doi:10.1186/1471-244x-13-59 23414364
21 de Graaf R, Kessler RC, Fayyad J, . The prevalence and effects of adult attention-deficit/hyperactivity disorder (ADHD) on the performance of workers: results from the WHO World Mental Health Survey Initiative. Occup Environ Med. Dec 2008;65(12):835–42. doi:10.1136/oem.2007.038448 18505771
22 Hechtman L, Swanson JM, Sibley MH, . Functional Adult Outcomes 16 Years After Childhood Diagnosis of Attention-Deficit/Hyperactivity Disorder: MTA Results. J Am Acad Child Adolesc Psychiatry. Nov 2016;55(11):945–952.e2. doi:10.1016/j.jaac.2016.07.774 27806862
23 Schein J, Adler LA, Childress A, . Economic burden of attention-deficit/hyperactivity disorder among adults in the United States: a societal perspective. J Manag Care Spec Pharm. Feb 2022;28(2):168–179. doi:10.18553/jmcp.2021.21290 34806909
24 Biederman J, Faraone SV, Spencer T, . Patterns of psychiatric comorbidity, cognition, and psychosocial functioning in adults with attention deficit hyperactivity disorder. Am J Psychiatry. Dec 1993;150(12):1792–8. doi:10.1176/ajp.150.12.1792 8238632
25 Dalsgaard S, Østergaard SD, Leckman JF, Mortensen PB, Pedersen MG. Mortality in children, adolescents, and adults with attention deficit hyperactivity disorder: a nationwide cohort study. Lancet. May 30 2015;385(9983):2190–6. doi:10.1016/s0140-6736(14)61684-6 25726514
26 Katzman MA, Bilkey TS, Chokka PR, Fallu A, Klassen LJ. Adult ADHD and comorbid disorders: clinical implications of a dimensional approach. BMC Psychiatry. Aug 22 2017;17(1):302. doi:10.1186/s12888-017-1463-3 28830387
27 Du Rietz E, Jangmo A, Kuja-Halkola R, . Trajectories of healthcare utilization and costs of psychiatric and somatic multimorbidity in adults with childhood ADHD: a prospective register-based study. J Child Psychol Psychiatry. Sep 2020;61(9):959–968. doi:10.1111/jcpp.13206 32115717
28 Rasmussen K, Palmstierna T, Levander S. Differences in Psychiatric Problems and Criminality Between Individuals Treated With Central Stimulants Before and After Adulthood. J Atten Disord. Jan 2019;23(2):173–180. doi:10.1177/1087054715571740 25795454
29 Schermann H, Gurel R, Ankory R, . Lower risk of fractures under methylphenidate treatment for ADHD: A dose-response effect. J Orthop Res. Dec 2018;36(12):3328–3333. doi:10.1002/jor.24129 30129682
30 Siffel C, DerSarkissian M, Kponee-Shovein K, . Suicidal ideation and attempts in the United States of America among stimulant-treated, non-stimulant-treated, and untreated patients with a diagnosis of attention-deficit/hyperactivity disorder. J Affect Disord. Apr 1 2020;266:109–119. doi:10.1016/j.jad.2020.01.075 32063553
31 Choi WS, Woo YS, Wang SM, Lim HK, Bahk WM. The prevalence of psychiatric comorbidities in adult ADHD compared with non-ADHD populations: A systematic literature review. PLoS One. 2022;17(11):e0277175. doi:10.1371/journal.pone.0277175 36331985
32 Johnson J, Morris S, George S. Managing comorbid Attention Deficit Hyperactivity Disorder (ADHD) in adults with Substance Use Disorder (SUD): what the addiction specialist needs to know. Addictive Disorders & their treatment. 2021;20(3):181–188.
33 Spera V, Pallucchini A, Maiello M, . Substance Use Disorder in Adult-Attention Deficit Hyperactive Disorder Patients: Patterns of Use and Related Clinical Features. Int J Environ Res Public Health. May 17 2020;17(10)doi:10.3390/ijerph17103509
34 Ivanov I, Bjork JM, Blair J, Newcorn JH. Sensitization-based risk for substance abuse in vulnerable individuals with ADHD: Review and re-examination of evidence. Neurosci Biobehav Rev. Apr 2022;135:104575. doi:10.1016/j.neubiorev.2022.104575 35151770
35 Piper BJ, Ogden CL, Simoyan OM, . Trends in use of prescription stimulants in the United States and Territories, 2006 to 2016. PLoS One. 2018;13(11):e0206100. doi:10.1371/journal.pone.0206100 30485268
36 Wilens TE, Adler LA, Adams J, . Misuse and diversion of stimulants prescribed for ADHD: a systematic review of the literature. J Am Acad Child Adolesc Psychiatry. Jan 2008;47(1):21–31. doi:10.1097/chi.0b013e31815a56f1 18174822
37 Faraone SV, Rostain AL, Montano CB, Mason O, Antshel KM, Newcorn JH. Systematic Review: Nonmedical Use of Prescription Stimulants: Risk Factors, Outcomes, and Risk Reduction Strategies. J Am Acad Child Adolesc Psychiatry. Jan 2020;59(1):100–112. doi:10.1016/j.jaac.2019.06.012 31326580
38 Harstad E, Levy S. Attention-deficit/hyperactivity disorder and substance abuse. Pediatrics. Jul 2014;134(1):e293–301. doi:10.1542/peds.2014-0992 24982106
39 Kooij SJ, Bejerot S, Blackwell A, . European consensus statement on diagnosis and treatment of adult ADHD: The European Network Adult ADHD. BMC Psychiatry. Sep 3 2010;10:67. doi:10.1186/1471-244x-10-67 20815868
40 Shrestha M, Lautenschleger J, Soares N. Non-pharmacologic management of attention-deficit/hyperactivity disorder in children and adolescents: a review. Transl Pediatr. Feb 2020;9(Suppl 1):S114–s124. doi:10.21037/tp.2019.10.01 32206589
41 Matthys F, Stes S, van den Brink W, . Guideline for screening, diagnosis and treatment of ADHD in adults with substance use disorders. International Journal of Mental Health and Addiction. 2014;12:629–647.
42 2021 National Survey on Drug Use and Health: Among the Veteran Population Aged 18 or Older
43 May T, Birch E, Chaves K, . The Australian evidence-based clinical practice guideline for attention deficit hyperactivity disorder. Australian & New Zealand Journal of Psychiatry. 2023;57(8):1101–1116.37254562
44 Dalrymple RA, McKenna Maxwell L, Russell S, Duthie J. NICE guideline review: Attention deficit hyperactivity disorder: diagnosis and management (NG87). Arch Dis Child Educ Pract Ed. Oct 2020;105(5):289–293. doi:10.1136/archdischild-2019-316928 31776172
45 Carpentier PJ, Levin FR. Pharmacological Treatment of ADHD in Addicted Patients: What Does the Literature Tell Us? Harv Rev Psychiatry. Mar/Apr 2017;25(2):50–64. doi:10.1097/hrp.0000000000000122 28272130
46 Cook J, Lloyd-Jones M, Arunogiri S, Ogden E, Bonomo Y. Managing attention deficit hyperactivity disorder in adults using illicit psychostimulants: A systematic review. Aust N Z J Psychiatry. Sep 2017;51(9):876–885. doi:10.1177/0004867417714878 28639480
47 Faraone SV, Wilens T. Does stimulant treatment lead to substance use disorders? J Clin Psychiatry. 2003;64 Suppl 11:9–13.
48 Humphreys KL, Eng T, Lee SS. Stimulant medication and substance use outcomes: a meta-analysis. JAMA Psychiatry. Jul 2013;70(7):740–9. doi:10.1001/jamapsychiatry.2013.1273 23754458
49 Martinez-Raga J, Knecht C, de Alvaro R, Szerman N, Ruiz P. Addressing dual diagnosis patients suffering from attention-deficit hyperactivity disorders and comorbid substance use disorders: A review of treatment considerations. Addictive Disorders & Their Treatment. 2013;12(4):213–230.
50 Özgen H, Spijkerman R, Noack M, . Treatment of Adolescents with Concurrent Substance Use Disorder and Attention-Deficit/Hyperactivity Disorder: A Systematic Review. J Clin Med. Aug 30 2021;10(17)doi:10.3390/jcm10173908
51 Weyandt LL, Oster DR, Marraccini ME, . Pharmacological interventions for adolescents and adults with ADHD: stimulant and nonstimulant medications and misuse of prescription stimulants. Psychol Res Behav Manag. 2014;7:223–49. doi:10.2147/prbm.S47013 25228824
52 Arnold LE, Hodgkins P, Caci H, Kahle J, Young S. Effect of treatment modality on long-term outcomes in attention-deficit/hyperactivity disorder: a systematic review. PLoS One. 2015;10(2):e0116407. doi:10.1371/journal.pone.0116407 25714373
53 Benson K, Flory K, Humphreys KL, Lee SS. Misuse of stimulant medication among college students: a comprehensive review and meta-analysis. Clin Child Fam Psychol Rev. Mar 2015;18(1):50–76. doi:10.1007/s10567-014-0177-z 25575768
54 Eaton C, Yong K, Walter V, Mbizvo GK, Rhodes S, Chin RF. Stimulant and non-stimulant drug therapy for people with attention deficit hyperactivity disorder and epilepsy. Cochrane Database Syst Rev. Jul 13 2022;7(7):Cd013136. doi:10.1002/14651858.CD013136.pub2 35844168
55 Elliott J, Johnston A, Husereau D, . Pharmacologic treatment of attention deficit hyperactivity disorder in adults: A systematic review and network meta-analysis. PLoS One. 2020;15(10):e0240584. doi:10.1371/journal.pone.0240584 33085721
56 Lee SS, Humphreys KL, Flory K, Liu R, Glass K. Prospective association of childhood attention-deficit/hyperactivity disorder (ADHD) and substance use and abuse/dependence: a meta-analytic review. Clin Psychol Rev. Apr 2011;31(3):328–41. doi:10.1016/j.cpr.2011.01.006 21382538
57 Lopez PL, Torrente FM, Ciapponi A, . Cognitive-behavioural interventions for attention deficit hyperactivity disorder (ADHD) in adults. Cochrane Database Syst Rev. Mar 23 2018;3(3):Cd010840. doi:10.1002/14651858.CD010840.pub2 29566425
58 Nanda A, Janga LSN, Sambe HG, . Adverse Effects of Stimulant Interventions for Attention Deficit Hyperactivity Disorder (ADHD): A Comprehensive Systematic Review. Cureus. Sep 2023;15(9):e45995. doi:10.7759/cureus.45995 37900465
59 Peterson K, McDonagh MS, Fu R. Comparative benefits and harms of competing medications for adults with attention-deficit hyperactivity disorder: a systematic review and indirect comparison meta-analysis. Psychopharmacology (Berl). Mar 2008;197(1):1–11. doi:10.1007/s00213-007-0996-4 18026719
60 Wilens TE, Woodward DW, Ko JD, Berger AF, Burke C, Yule AM. The Impact of Pharmacotherapy of Childhood-Onset Psychiatric Disorders on the Development of Substance Use Disorders. J Child Adolesc Psychopharmacol. May 2022;32(4):200–214. doi:10.1089/cap.2022.0016 35587209
61 Balduzzi S, Rücker G, Schwarzer G. How to perform a meta-analysis with R: a practical tutorial. BMJ Ment Health. 2019;22(4):153–160.
62 Guyatt GH, Oxman AD, Vist GE, . GRADE: an emerging consensus on rating quality of evidence and strength of recommendations. Bmj. Apr 26 2008;336(7650):924–6. doi:10.1136/bmj.39489.470347.AD 18436948
63 Biederman J, Monuteaux MC, Spencer T, Wilens TE, Macpherson HA, Faraone SV. Stimulant therapy and risk for subsequent substance use disorders in male adults with ADHD: a naturalistic controlled 10-year follow-up study. Am J Psychiatry. May 2008;165(5):597–603. doi:10.1176/appi.ajp.2007.07091486 18316421
64 Chang Z, Lichtenstein P, Halldner L, . Stimulant ADHD medication and risk for substance abuse. J Child Psychol Psychiatry. Aug 2014;55(8):878–85. doi:10.1111/jcpp.12164 25158998
65 Dalsgaard S, Mortensen PB, Frydenberg M, Thomsen PH. ADHD, stimulant treatment in childhood and subsequent substance abuse in adulthood - a naturalistic long-term follow-up study. Addict Behav. Jan 2014;39(1):325–8. doi:10.1016/j.addbeh.2013.09.002 24090624
66 Mannuzza S, Klein RG, Truong NL, . Age of methylphenidate treatment initiation in children with ADHD and later substance abuse: prospective follow-up into adulthood. Am J Psychiatry. May 2008;165(5):604–9. doi:10.1176/appi.ajp.2008.07091465 18381904
67 Steinhausen HC, Bisgaard C. Substance use disorders in association with attention-deficit/hyperactivity disorder, co-morbid mental disorders, and medication in a nationwide sample. Eur Neuropsychopharmacol. Feb 2014;24(2):232–41. doi:10.1016/j.euroneuro.2013.11.003 24314850
68 Torgersen T, Gjervan B, Rasmussen K, Vaaler A, Nordahl HM. Prevalence of comorbid substance use disorder during long-term central stimulant treatment in adult ADHD. Atten Defic Hyperact Disord. Mar 2013;5(1):59–67. doi:10.1007/s12402-012-0094-2 23104523
69 Wilens TE, Gignac M, Swezey A, Monuteaux MC, Biederman J. Characteristics of adolescents and young adults with ADHD who divert or misuse their prescribed medications. J Am Acad Child Adolesc Psychiatry. Apr 2006;45(4):408–14. doi:10.1097/01.chi.0000199027.68828.b3 16601645
70 Kast KA, Rao V, Wilens TE. Pharmacotherapy for Attention-Deficit/Hyperactivity Disorder and Retention in Outpatient Substance Use Disorder Treatment: A Retrospective Cohort Study. J Clin Psychiatry. Feb 23 2021;82(2)doi:10.4088/JCP.20m13598
71 Konstenius M, Jayaram-Lindström N, Beck O, Franck J. Sustained release methylphenidate for the treatment of ADHD in amphetamine abusers: a pilot study. Drug Alcohol Depend. Apr 1 2010;108(1–2):130–3. doi:10.1016/j.drugalcdep.2009.11.006 20015599
72 Levin FR, Evans SM, Brooks DJ, Garawi F. Treatment of cocaine dependent treatment seekers with adult ADHD: double-blind comparison of methylphenidate and placebo. Drug Alcohol Depend. Feb 23 2007;87(1):20–9. doi:10.1016/j.drugalcdep.2006.07.004 16930863
73 Levin FR, Evans SM, Brooks DJ, Kalbag AS, Garawi F, Nunes EV. Treatment of methadone-maintained patients with adult ADHD: double-blind comparison of methylphenidate, bupropion and placebo. Drug Alcohol Depend. Feb 1 2006;81(2):137–48. doi:10.1016/j.drugalcdep.2005.06.012 16102908
74 Levin FR, Mariani JJ, Specker S, . Extended-Release Mixed Amphetamine Salts vs Placebo for Comorbid Adult Attention-Deficit/Hyperactivity Disorder and Cocaine Use Disorder: A Randomized Clinical Trial. JAMA Psychiatry. Jun 2015;72(6):593–602. doi:10.1001/jamapsychiatry.2015.41 25887096
75 Notzon DP, Mariani JJ, Pavlicova M, . Mixed-amphetamine salts increase abstinence from marijuana in patients with co-occurring attention-deficit/hyperactivity disorder and cocaine dependence. Am J Addict. Dec 2016;25(8):666–672. doi:10.1111/ajad.12467 28051838
76 Schubiner H, Downey KK, Arfken CL, . Double-blind placebo-controlled trial of methylphenidate in the treatment of adult ADHD patients with comorbid cocaine dependence. Experimental and clinical psychopharmacology. 2002;10(3):286.12233989
77 HHS, SAMHSA Release 2022 National Survey on Drug Use and Health Data
78 Garnier LM, Arria AM, Caldeira KM, Vincent KB, O’Grady KE, Wish ED. Sharing and selling of prescription medications in a college student sample. J Clin Psychiatry. Mar 2010;71(3):262–9. doi:10.4088/JCP.09m05189ecr 20331930
79 Chen LY, Crum RM, Strain EC, Alexander GC, Kaufmann C, Mojtabai R. Prescriptions, nonmedical use, and emergency department visits involving prescription stimulants. J Clin Psychiatry. Mar 2016;77(3):e297–304. doi:10.4088/JCP.14m09291 26890573
80 Loskutova NY, Waterman J, Callen E, Staton EW, Bullard E, Shields J. Knowledge, Attitudes, and Practice Patterns of Health Professionals Toward Medical and Non-medical Stimulant Use by Young Adults. J Am Board Fam Med. Jan–Feb 2020;33(1):59–70. doi:10.3122/jabfm.2020.01.190071 31907247
81 Najib J. The efficacy and safety profile of lisdexamfetamine dimesylate, a prodrug of d-amphetamine, for the treatment of attention-deficit/hyperactivity disorder in children and adults. Clin Ther. Jan 2009;31(1):142–76. doi:10.1016/j.clinthera.2009.01.015 19243715
82 Epstein JN, Weiss MD. Assessing treatment outcomes in attention-deficit/hyperactivity disorder: a narrative review. Prim Care Companion CNS Disord. 2012;14(6)doi:10.4088/PCC.11r01336
83 Chamakalayil S, Strasser J, Vogel M, Brand S, Walter M, Dürsteler KM. Methylphenidate for Attention-Deficit and Hyperactivity Disorder in Adult Patients With Substance Use Disorders: Good Clinical Practice. Front Psychiatry. 2020;11:540837. doi:10.3389/fpsyt.2020.540837 33574770
84 Baweja R, Mattison RE, Waxmonsky JG. Impact of Attention-Deficit Hyperactivity Disorder on School Performance: What are the Effects of Medication? Paediatr Drugs. Dec 2015;17(6):459–77. doi:10.1007/s40272-015-0144-2 26259966
85 Harpin V, Mazzone L, Raynaud JP, Kahle J, Hodgkins P. Long-Term Outcomes of ADHD: A Systematic Review of Self-Esteem and Social Function. J Atten Disord. Apr 2016;20(4):295–305. doi:10.1177/1087054713486516 23698916