# ACKNOWLEDGMENTS

The authors are grateful to Cheryl Banick, MLIS, and Gaelen Adam, MLIS, for literature searching and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Eric Hermes, MD
  National Director, Psychopharmacology and Somatic Treatments
  VA Office of Mental Health
- Daina Wells, PharmD, MBA, BCPS, BCPP
  Assistant Chief Consultant
  PBM Academic Detailing Service, VA
- Matthew J. Barry, DO
  Co-Chief of Psychiatry
  VA Finger Lakes Healthcare System
- Matthew Schreiber, MD, PhD
  Psychiatrist
  Seattle VA Medical Center
- Robert Shura, PsyD, ABPP-CN
  Neuropsychologist
  W.G. (Bill) Hefner VA Medical Center
- Jonathan S. Emens M.D., F.A.B.S.M.
  Chief of Psychiatry
  VAPORHCS

## Technical Expert Panel

To ensure robust, scientifically relevant work, the technical expert panel (TEP) guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members included:

- Elisa Gumm, DO
  Physician
  Tucson VA Medical Center
- Mark Sandberg, PhD, ABPP, ABN
  Neuropsychologist
  Northport VA Medical Center
- Andrew Saxon, MD
  Director
  Center of Excellence in Substance Abuse Treatment and Education (CESATE), VA Puget Sound Health Care System
  Professor
  Department of Psychiatry and Behavioral Sciences, UW Medicine
- Cynthia Smith-Seidel, PhD
  Psychologist
  Martinsburg VA Medical Center