# Executive Summary

KEY FINDINGS

The effect of stimulants on the incidence of substance use disorders (SUD), misuse, and diversion in people with attention-deficit/hyperactivity disorder (ADHD) without SUD at baseline:

► Seven studies (4 single group and 3 non-randomized comparative) examined the incidence of SUD development among people with ADHD who were prescribed stimulant medication.
► Among people prescribed stimulants for ADHD, 5 studies found that approximately 1 in 7 adults (14%, 95% CI [2%, 35%]) is newly diagnosed with SUD (ie, any substance), though estimates varied drastically across studies (no evidence grading). There was insufficient evidence to pool estimates for the incidence of alcohol-specific use disorders (AUD) or non-alcohol substance use disorders or stimulant use disorders among people prescribed stimulants for ADHD.
► Only 1 small single-group study assessed diversion or misuse of stimulants in a sample of adolescents and college-age adults prescribed stimulants for ADHD. Diversion was reported in 11% of people and misuse in 10% to 31% depending on definition (no evidence grading).
► Among people prescribed stimulants for ADHD compared to people with ADHD who are not prescribed stimulants, there is no evidence of a difference in the risk of a new SUD in adulthood (low confidence).
► Among people prescribed stimulants for ADHD compared to those who are not prescribed stimulants, there is insufficient evidence for a difference in the risk of AUD or non-alcohol substance use or stimulant use disorders (no conclusions).

The effect of stimulants on ADHD and SUD symptom and treatment outcomes in people with co-occurring ADHD and SUD:

► Seven studies (1 non-randomized comparative study and 6 randomized controlled trials) examined the benefits and harms of ADHD stimulant medication plus cognitive behavioral therapy or skills training among people with co-occurring ADHD and SUD compared to those who received cognitive behavioral therapy or skills training and were not prescribed stimulant medications.
► Among people with co-occurring ADHD and SUD who are prescribed versus not prescribed stimulants, there is no evidence of a difference in ADHD treatment adherence, substance use, SUD symptom change, and abstinence (all conclusions with low confidence).
► Among people with co-occurring ADHD and SUD who are prescribed versus not prescribed stimulants, there is insufficient evidence (no conclusion) to assess differences in ADHD symptom change, SUD treatment adherence, misuse or diversion, and depression/anxiety.

Overall clinical implications:

► Prescribing stimulants to people with ADHD may have no effect on the risk of subsequent SUD. Available studies did not identify broad evidence of harm associated with the prescription of stimulants for people with ADHD. There are limited data about misuse and diversion of stimulant medications in people with ADHD. Prescribers should consider stimulant medications or other treatments for ADHD after a thorough, individualized risk-benefit discussion.

Attention-deficit/hyperactivity disorder (ADHD) is a neurodevelopmental disorder that has been recorded in the medical literature for the last 2 centuries under various names. Most research on ADHD has focused on children, but over the past decade there has been an increase in the documented prevalence and incidence of ADHD among adults. Prescription psychostimulants are first-line pharmacologic treatments for ADHD in adults. However, there is concern for misuse and diversion of psychostimulants, and concern that these medications may lead to a new substance use disorder (SUD) diagnosis or precipitate substance-related problems in people with co-occurring SUD and ADHD. Though existing systematic reviews have examined the use of stimulant medications in ADHD, none have focused exclusively on diagnosed SUD.

## CURRENT REVIEW

The Veterans Health Administration (VHA) Office of Mental Health (OMH) requested the present evidence review on the incidence of SUD in adults with ADHD who are prescribed psychostimulant medications as well as the benefits and harms of psychostimulant treatment of ADHD in adults with comorbid SUD. The following key questions (KQ) were developed in collaboration with VA partners:

1. Among adults diagnosed with ADHD and prescribed psychostimulant medications, what is the incidence of misuse of the prescribed medications, the incidence of diversion of the prescribed medications, and the incidence of SUD in this population?
2. Among adults diagnosed with ADHD with a co-occurring SUD, what are the benefits and harms of non-stimulant ADHD pharmacological and/or nonpharmacological treatment of ADHD compared to ADHD psychostimulant medications?

We searched for peer-reviewed articles in Medline (via PubMed), Embase, and PsycINFO from inception to December 14, 2023. Eligible studies included people diagnosed with ADHD using Diagnostic and Statistical Manual of Mental Disorders (DSM)-IV through DSM 5-TR or comparable criteria. For KQ 1, our focus was on reporting incident SUD diagnosis or misuse or diversion of prescribed psychostimulants in adulthood. We excluded cross-sectional designs, and studies that only evaluated self-reported substance use and not SUD diagnoses. Outcomes of interest needed to be assessed in people ≥18 years of age. We included randomized controlled trials (RCT), nonrandomized comparative studies (NRCS), and single-group studies. To evaluate the overall incidence of SUD, we analyzed the stimulant arms from comparative studies and single-group studies. We used comparative studies to determine whether taking stimulant medication for ADHD increases the risk of SUD diagnosis in people without SUD at baseline. For KQ 2, eligible studies (RCT or NRCS) compared stimulant treatment alone to other ADHD treatments, placebo, or no treatment in people with both ADHD and SUD.

Seven studies (3 NRCS and 4 single group) reported the incidence of SUD in people prescribed stimulants with ADHD who did not have SUD at baseline, and 7 studies (6 RCTs and 1 NRCS) compared stimulant treatment to other ADHD treatments in people with both ADHD and SUD. Most studies were conducted in the United States (N = 9), followed by Denmark (N = 2), Sweden (N = 2), and Norway (N = 1). ADHD was defined using the DSM-IV-TR (N = 6), DSM III-R (later reassessed using the DSM-IV) (N = 2), ICD-10 codes (N = 2), Conners’ Adult ADHD self and observer rating scales (N = 1), by a regional expert committee (N = 1), or some combination of these (N = 2).

### Effect of Stimulants on the Incidence of SUD, Misuse, and Diversion in People with ADHD Without SUD at Baseline

Seven studies (3 NRCS and 4 single group) conducted between 1970 and 2010 (3 studies did not report dates of enrollment) included 58,077 people and reported on the incidence of SUD in people with ADHD taking stimulant medications. Three studies were conducted in the US, 2 in Denmark, 1 in Norway, and 1 in Sweden. Methylphenidate was the most used stimulant (N = 6), followed by dexamphetamine (N = 2), amphetamine products (N = 2), and pemoline (N = 1). Only 2 studies reported information on dosing (1 study reported a mean dose 41.7 mg of methylphenidate and another study a mean maximum dose of 58.7 mg). Across 5 studies, the length of follow-up ranged from 3 to 19 years, with 4 of these having 10 or more years of follow-up. Two studies did not report the length of follow-up. Two studies reported loss to follow-up of 15% and 20%, and 4 studies reported stimulant treatment duration between 2 to 6 years. At baseline, the age of people was between 6 and 46 years old (4 studies enrolled people <18 years of age and followed them until adulthood). Four studies (1 NRCS and 3 single group) had medium risk of bias due to not clearly reporting whether outcome assessors were blind and had at least 1 additional concern (high attrition, inclusion of only people with high ADHD severity that may not be representative of the average ADHD population, and unclear reporting of comparator representativeness). Three studies had no concerns about bias.

Studies reported various substance use disorder outcomes for KQ 1. Two studies reported SUD (ie, any substance), and 3 studies reported alcohol use disorder (AUD) diagnosis separately from SUDs. Finally, 2 studies reported non-alcohol substance use disorders or stimulant use disorders. When studies reported SUD, AUD, or other non-alcohol substance use disorders, it was not always clear whether these were mutually exclusive.

In summary, 14% (95% CI [(2%, 35%]) of people had a new SUD diagnosis after being prescribed stimulants for ADHD (5 studies). There were insufficient data to pool estimates for AUD or non-alcohol substance use or stimulant use disorder for people with ADHD prescribed stimulant medications. Only 1 small study reported on prescription stimulant diversion, with 11% of enrollees self-reporting diversion. The same study found that 22% of people took too much of their prescribed medication or misused it in some way, 10% got high on their medication, 16% skipped their medication to use alcohol or drugs, 31% used their medications with alcohol, and 5% experienced a reaction when using their ADHD medication and alcohol or drugs. We did not grade evidence for these outcomes.

In studies that compared those with ADHD prescribed stimulant medications to those who were not prescribed stimulant medications, there was no evidence of a difference for SUD outcomes (2 studies) (low confidence). In addition, studies provide insufficient evidence (no conclusion) for AUD, non-alcohol substance use disorder, or stimulant use disorder for people with ADHD prescribed stimulant medications compared to those who were not prescribed stimulant medications (due to limited studies meeting inclusion criteria). Comparative studies did not assess diversion or misuse.

### Effect of Stimulants on ADHD and SUD Symptom and Treatment Outcomes in People with Co-Occurring ADHD and SUD

Seven studies (6 RCTs and 1 NRCS) conducted between 1998 and 2020 (2 studies did not report dates) analyzed 662 people and examined the effect of stimulant treatment on people with ADHD and SUD. The studies included people with a comorbid SUD (N = 1), cocaine or amphetamine use disorder (N = 5), or people receiving methadone treatment for opioid use disorder (N = 1). Six studies were conducted in the US and 1 in Sweden. Four RCTs compared methylphenidate (dose range 40-90 mg/day) to placebo, 2 RCTs compared extended-release mixed amphetamine salts (60 and/or 80 mg daily) to placebo, 1 RCT included a third comparison group of bupropion, and 1 NRCS compared any stimulant (dose not reported) to non-stimulant ADHD treatment or those receiving no treatment. In the 6 RCTs, all groups also received either cognitive behavioral therapy (CBT) or individual skills training targeted at substance use during the study. Treatment duration in the RCTs was between 12 and 14 weeks and in the NRCS was approximately 2 years. In the RCTs, loss to follow-up ranged from 25% to 57%. The NRCS did not report loss to follow-up. The mean age of people at baseline was between 37 and 40 years. Four RCTs had medium risk of bias due to not blinding outcome assessors and high attrition. Two RCTs had no methodological concerns. The NRCS had high risk of bias due to conducting crude analyses and not clearly reporting sample eligibility.

In summary, there was no evidence of a difference in ADHD medication treatment adherence (4 studies), substance use (5 studies), SUD symptom change (2 studies), or abstinence from substance use (5 studies) in people with co-occurring ADHD and SUD who are prescribed stimulants with CBT or skills training versus their counterparts not prescribed stimulants but who received CBT or skills training (low confidence for all). Studies provide insufficient evidence (no conclusion) for ADHD symptom change, SUD treatment adherence (2 studies), medication misuse/diversion (1 study), and measures of depression and anxiety (1 study) due to imprecise estimates, inconsistent estimates, and/or methodological limitations. There was no evidence of a difference in various measures of adverse events (4 studies; no evidence grading).

## DISCUSSION

In 7 studies that included 58,077 people, there was wide variation in the incidence proportion of SUD (range = 0.00–0.53) among people with ADHD prescribed stimulants. Importantly, 2 of 3 comparative studies found no significant difference in new SUD diagnoses for people with ADHD between those who were or were not prescribed stimulants. One study (NRCS) reported a higher incidence proportion of SUD in ADHD people treated with mixed medications (combination of stimulants and other medications); however, this study did not clearly report patient characteristics, such as psychiatric comorbidities. The same study reported no significant difference in the incident proportion of SUD diagnoses between the methylphenidate-alone group and those who had never received medication. Therefore, it is possible people who received mixed medications may represent those with other comorbidities that may increase the risk of SUD. Given the available data, we concluded that among people prescribed stimulants for ADHD compared to people with ADHD who are not prescribed stimulants, there is no evidence of a difference in the risk of developing an SUD, and evidence was insufficient to assess the effect of stimulant medications on AUD and other non-alcohol SUD.

For people with comorbid ADHD and SUD at baseline, studies showed mixed findings on health outcomes of interest for those treated with stimulants with CBT or skills training compared to placebo with CBT or skills training. For example, 5 RCTs showed either significant improvements or no difference in changes in ADHD symptoms between those treated with stimulants compared to placebo and CBT or skills training. Studies used different measures for symptom change and had small samples, which complicated interpretation of these findings. Further, there was no evidence of a difference in substance use, SUD symptoms, and abstinence from substances for those with comorbid ADHD and SUD prescribed stimulants compared to those not receiving these medications. Importantly, the included studies had small sample sizes and utilized older drug formulations that may have higher potential for misuse.

### Implications for VA

Given the increasing rates of ADHD diagnoses in the Veteran population, the VA needs to provide guidance, and education is necessary for clinicians treating ADHD. Fears that the use of stimulant medications in adults with ADHD can lead to a new SUD diagnosis or precipitate substance-related problems in people with co-occurring SUD and ADHD appear not to be supported by the overall evidence. Although no study was explicitly conducted in Veterans or the VA, many of the findings and conclusions likely translate to the VA. This systematic review did not identify broad evidence of harm associated with the prescription of stimulants for people with ADHD. Therefore, prescribers should consider stimulant treatment or other treatments for ADHD after a thorough, individualized risk-benefit discussion in collaboration with members of the care team. Considerations about prescription medications should include ADHD symptom severity and comorbidities, as well as social supports and provider consultation. Further, given the advances in these medications, prescribers should also consider newer formulations that may still provide symptom benefit while simultaneously offering lower misuse potential. Though evidence was minimal, given the risk for diversion or misuse of these medications, prescriptions should include broad education about the risks of diversion and/or misuse of these medications and may benefit from strategies used in opiate use disorder treatment to reduce these risks (eg, ongoing toxicology screens and/or use of bottle recall/pill counts).

### Future Research

There are limited longitudinal data on the relationship between psychostimulant treatment for ADHD and SUD outcomes in adulthood. Longitudinal cohorts with ample sample size and follow-up are needed to examine the long-term outcomes of stimulant exposure as it relates to substance use. To partially fill this gap, researchers could use VA electronic health records to examine long-term outcomes for Veterans prescribed stimulants. Using all payer claims data may provide another option to fill gaps on the long-term use of stimulants, with a particular focus on following people from childhood to adulthood. Additional longitudinal data are needed on diversion or misuse outcomes in adulthood. These outcomes may be more challenging to evaluate with routinely captured health data (eg, claims) and would require establishing new cohorts or adding survey questions to existing cohorts. Alternatively, to answer the question of whether ADHD stimulant medication use may impact incidence of SUD, predictive modeling studies may be needed to help identify which people may be at increased risk for SUD outcomes. There is also an opportunity for qualitative research to understand the factors that contribute to diversion and misuse. Studies on co-occurring ADHD and SUD largely included people with stimulant use disorders, small sample sizes and old formulations of stimulants. There is a need for sufficiently powered randomized trials of people with ADHD and SUD and modern formulations of stimulants, such as extended release compounds. Research on people with drug-specific substance use disorders (eg, alcohol and opioid) is also needed. Finally, there is a need to standardize the collection of outcome measures. The included studies evaluated multiple measures, and even when studies used the same measure, they varied in analyzing them as continuous or categorical outcomes.

### Limitations

This evidence review has several limitations. We required that outcomes for KQ 1 and baseline population for KQ 2 include SUD diagnosis, not just substance use. By requiring inclusion of people with diagnoses of SUD, the results of this report may not generalize to people with ADHD who endorse substance-related problems but are either subthreshold or have not formally received an SUD diagnosis. We also included ADHD and SUD definitions from several versions of the DSM, as well as ICD or other similar diagnostic methods. These definitions are different in terms of criteria needed to fulfill these diagnoses, so it may be possible that the people included are not homogenous across studies in terms of their symptoms. Importantly, many of the studies included used older stimulant medications (eg, immediate release formulas), which may have higher side effects or misuse potential. Relating to diversion and misuse, we only included longitudinal studies and those with outcomes in adult populations, which would have excluded any published cross-sectional studies or those that focused on misuse or diversion in non-adult populations. Further, for studies examining outcomes in people with comorbid ADHD and SUD, as previously mentioned, these studies included small sample sizes that may have impacted many of these outcomes reaching statistical significance.

## CONCLUSIONS

Among people prescribed stimulants for ADHD, approximately 1 in 7 is newly diagnosed with SUD. However, the overall evidence does not indicate that stimulant medication treatment for ADHD increases the risk of SUD diagnoses. There is sparse longitudinal data on new onset AUD, or non-alcohol substance use disorders. Little is known about the risk of diversion or misuse among people prescribed stimulants for ADHD.

For people with co-occurring ADHD and SUD, there is no evidence of a difference in ADHD treatment adherence, substance use, SUD symptom change, or abstinence from SUD between those treated with stimulants and those receiving other forms of care. For the same comparison, there is insufficient evidence to assess ADHD symptom change, SUD treatment adherence, and medication misuse or diversion.

Longitudinal data or predictive modeling studies are needed to fill the evidence gap on ADHD medication diversion or misuse among people prescribed stimulants for ADHD. New comparative evidence is needed to assess the effects of stimulants on SUD treatment adherence, and medication misuse or diversion among people with co-occurring ADHD and SUD. Future studies should use a standardized set of measures to evaluate ADHD and SUD related symptoms.