# DISCUSSION

We identified 7 longitudinal studies that reported on incident SUD, and diversion or misuse among people with ADHD prescribed stimulants. Three of these 7 studies also evaluated the risk of incident SUD in people prescribed stimulant medications compared to those not prescribed stimulants. In addition, we identified 7 studies that compared stimulants in people with co-occurring ADHD and SUD. Key findings include the following:

## KEY FINDINGS

For the effect of stimulants on the incidence of SUD, misuse, and diversion in people with ADHD without SUD at baseline, key findings are:

- Among people prescribed stimulants for ADHD, 5 studies found that approximately 1 in 7 adults (14%, 95% CI [2%, 35%]) is newly diagnosed with SUD (ie, any substance), though estimates varied drastically across studies (no evidence grading). There was insufficient evidence to pool estimates for the incidence of AUD or non-alcohol substance use disorders or stimulant use disorders among people prescribed stimulants for ADHD.
- Only 1 small single group study assessed diversion or misuse of stimulants among adolescents and college-age adults prescribed stimulants for ADHD. Diversion was reported in 11% of people and misuse in 10% to 31% depending on definition (no evidence grading).
- Among people prescribed stimulants for ADHD compared to people with ADHD who are not prescribed stimulants, there is no evidence of a difference in the risk of a new SUD in adulthood (low confidence).
- Among people prescribed stimulants for ADHD compared to those who are not prescribed stimulants, there is insufficient evidence for a difference in the risk of AUD or non-alcohol substance use or stimulant use disorders (no conclusions).

For the effect of stimulants on ADHD and SUD symptom and treatment outcomes in people with co-occurring ADHD and SUD, key findings are:

- Among people with co-occurring ADHD and SUD who are prescribed versus not prescribed stimulants, there is no evidence of a difference in ADHD treatment adherence, substance use, SUD symptom change, and abstinence (all conclusions with low confidence).
- Among people with co-occurring ADHD and SUD who are prescribed versus not prescribed stimulants, there is insufficient evidence (no conclusion) to assess differences in ADHD symptom change, SUD treatment adherence, misuse or diversion, and depression/anxiety.

The overall clinical implications of these findings are as follows:

- Prescribing stimulants to people with ADHD may have no effect on the risk of subsequent SUD. Available studies did not identify broad evidence of harm associated with the prescription of stimulants for people with ADHD. There are limited data about misuse and diversion of stimulant medications in people with ADHD. Prescribers should consider stimulant medications or other treatments for ADHD after a thorough, individualized risk-benefit discussion.

The incidence proportion of SUD and AUD varied widely in the 7 studies of people with ADHD prescribed stimulants. While not an exact comparison, an estimated 17.3% (prevalence) of the US adult population had an SUD diagnosis in 2022,^77^ which is comparable to the pooled 14% SUD incidence proportion reported in the 7 studies identified in this report.

Importantly, 2 comparative studies found no significant difference in incident SUD for people with ADHD between those who were or were not prescribed stimulants. One of these NRCS also reported a higher incidence of SUD in people with ADHD treated with mixed medications, which included combinations of stimulants and other medications, compared to those treated with no medications.^67^ However, these data came from an observational study that reported whether medications were prescribed during the entire study period in people with other psychiatric comorbidities; therefore, it is possible that this group of people may represent those with other comorbidities that may have an increased risk of SUD. This same study reported that those who had taken methylphenidate alone had no significant differences in SUD outcomes compared with those who had never received medication.

Although our review found no clear benefits of stimulant treatment on reducing the risk of SUD, most studies found no evidence for increased risk of SUD or AUD when compared to other ADHD treatment groups. Only 1 single-group study reported on longitudinal outcomes of diversion or misuse of ADHD medications in people without SUD at baseline. Diversion was relatively low (11%), and approximately 22% reported misusing their ADHD medications or using too much, and 31% reported using their ADHD medication with other substances, such as alcohol. Importantly, this was a small study of adolescents and college-age adults, so findings may not generalize to adults with ADHD. Diversion and non-medical use of ADHD stimulant medications have been reported amongst younger age groups, including college students.^78^ Another study reported that alcohol, illicit drugs, or another medication was present in approximately half of all emergency department visits for ADHD medications in the US in people ages 12 and older.^79^ Educating patients about the potential harms of medication misuse, including non-medical use, is important. Although many health providers agree that part of their responsibility is to educate patients about medications, a recent survey of family physicians and college health professionals found that less than 75% felt it was their responsibility to educate patients on the legal risks of misuse or on the effects of misuse on social lives or other relationships.^80^

For people with comorbid ADHD and SUD at baseline, 5 RCTs reported on changes in ADHD symptoms between those treated with stimulants compared to placebo. Two of these studies reported significant improvements in ADHD symptoms for those in the treatment group compared to placebo, and 3 other RCTs found no significant differences between groups in terms of ADHD symptom change. One RCT also reported no significant difference between those treated with a stimulant medication compared to a non-stimulant ADHD medication. Importantly, the evidence base on the effects of stimulants for people ADHD and SUD needs to be interpreted in context. First, the sample sizes for these studies were relatively small, which may have impacted the precision of estimates. It is possible that several of these “non-significant” outcomes may not have reached statistical significance due to the small sample sizes of these studies. Second, virtually all the trials are old and use medications that are now less commonly prescribed, such as immediate release formulations that have largely been superseded by extended-release formulations and/or prodrugs.^81^ Newer formulations have both improved efficacy and reduced side effects/misuse potential that make them well suited for treatment of ADHD in people with SUDs due to their lower misuse potential. Third, studies utilized different measures for symptom change assessment. Even when studies used the same measure, such as the CAARS, they used the assessment differently, such as only using specific subscales. Previous reviews of ADHD symptom assessments have emphasized the need for assessing a broader definition of symptoms, including quality of life and measures of functioning.^82^ The variety of assessments used in the included studies may not have captured the full range of potential symptom change that may accompany medication use. Fourth, we concluded that overall, evidence is insufficient for reduction of ADHD symptoms in people with co-occurring ADHD and SUD treated with stimulant medication compared to no stimulants. However, this conclusion does not consider the much larger evidence base showing efficacy of these medications in people with ADHD without SUDs. People with co-occurring ADHD and SUD may be more complex in terms of other factors that may impact ADHD symptoms.

In terms of treatment adherence, 3 studies that included people with comorbid ADHD and SUD reported no significant difference in ADHD treatment adherence based on urine toxicology screens for those assigned to stimulant treatment compared to placebo. Additionally, 1 study reported no significant differences in treatment retention when comparing stimulant to non-stimulant medications among those who completed the treatment course. Relatedly, only 1 study reported lower medication tolerance among those taking stimulant medications compared to those taking placebo. There were no other significant differences in tolerance reported or treatment discontinuation due to side effects. Overall, there appears to be no significant differences in medication adherence in those prescribed stimulants with CBT compared to placebo with CBT.

Overall, there was no evidence of a difference in ADHD treatment adherence, substance use, SUD symptoms, and abstinence from substances for stimulant treatment with CBT in those with comorbid ADHD and SUD when compared to those not receiving these medications and CBT. For SUD treatment adherence, 1 study reported that those in an outpatient treatment program for SUD who received ADHD medication within 90 days had lower attrition in the SUD treatment program. While a different RCT reported no difference in the number of relapse-prevention-focused CBT sessions attended between treatment and control groups, this same study reported greater odds of abstinence in those receiving stimulant treatment compared to placebo.^74^ Four other studies reported no difference in abstinence outcomes. Additionally, for substance use, other than potential increased use of cannabis products,^72^ no increased risk of substance use was reported. One RCT reported lower opiate use in people taking methylphenidate compared to placebo. Another study reported fewer days of <60 g alcohol consumption for those taking stimulants compared to placebo, but no differences in >60 g consumption. Two other studies examining cannabis/THC use reported mixed outcomes, with one reporting higher use and another reporting lower use in those taking stimulant medications versus placebo. No other significant differences were reported between treatment and placebo groups.

### Strengths and Limitations of the Systematic Review Process

There are several limitations to the current review. For KQ 1, we required that outcomes include SUD diagnosis according to the DSM or similar criteria, not just substance use. Similarly, for KQ 2, we required that those included have a diagnosis of both ADHD and SUD using the DSM or similar criteria. By requiring inclusion of people with diagnoses of SUD, the results of this report may not be relevant to people with ADHD with subthreshold substance-related problems or who have not formally received an SUD diagnosis. Requiring a diagnosis of SUD meant that standardized criteria was used across studies to identify substance use. We also included ADHD and SUD definitions from several versions of the DSM, as well as ICD or other similar diagnostic methods, and these definitions are different in terms of criteria needed to fulfill these diagnoses. Therefore, it may be possible that the people included are not homogenous across studies in terms of their symptoms. However, restricting these definitions to only the DSM-5 would have limited the literature base further and may not account for changes in the understanding of these diagnoses. Relating to diversion and misuse, we only included longitudinal studies and those with outcomes in adult populations, which would have excluded any published cross-sectional studies or those that focused on misuse or diversion in non-adult populations. Additionally, during our abstract screening process, we required that abstracts explicitly state that they included people with ADHD and included information about stimulant use. These screening methods may have missed studies that were relevant to our study but were not explicit about these inclusion criteria in the abstract.

### Implications for VA

Given the increasing rates of ADHD diagnoses in the Veteran population, the VA needs to provide guidance and education for clinicians treating ADHD. First and foremost, the evidence base related to these questions for VA policy and practice is remarkably thin (no study was conducted in the VA) and must be supplemented with additional research to increase confidence in these key areas of interest among a Veteran population. That said, fears that the use of stimulant medications in adults with ADHD can lead to a new SUD diagnosis or precipitate substance-related problems in people with co-occurring SUD and ADHD appear not to be supported by the overall evidence. Absent more evidence of harm (ie, incident SUD diagnoses and/or increases in substance-related problems in people with co-occurring SUD and ADHD), prescribers should consider stimulant and non-stimulant medications for the treatment of adult ADHD after a thorough, individualized risk-benefit discussion. Considerations about prescription medications should include ADHD symptom severity, comorbidities, as well as social supports and provider consultation. Further, given the advances in these medications, prescribers should also consider newer formulations that may provide symptom benefit and simultaneously offer lower misuse potential.^83^ Though evidence was minimal, given the risk for diversion or misuse of these medications, prescriptions should include broad education about the risks of diversion and/or misuse of these medications and may benefit from strategies used in opiate use disorder treatment to reduce these risks (eg, ongoing toxicology screens and/or use of bottle recall/pill counts).

## FUTURE RESEARCH

This review highlights the limited data on the relationship between psychostimulant treatment for ADHD and SUD outcomes in adulthood. Additional longitudinal studies are needed to examine the long-term outcomes of stimulant exposure as it relates to substance use. Moreover, these studies need to explore not only exposure to stimulants, but timing and dose of stimulant exposure as well. While the scope of the current review did not include specific examination of age at first prescription or duration of stimulant exposure, these may be important factors related to SUD outcomes. For instance, lack of treatment throughout childhood and adolescence may lead to academic and social impairments, and these problem behaviors may be well engrained before ADHD treatment has a chance to improve occupational or social functioning.^84,^ ^85^ We also identified only 1 longitudinal study that reported on diversion or misuse outcomes in adulthood. Additional longitudinal studies are needed to understand misuse and diversion outcomes, as well as risk factors for these within patient groups prescribed psychostimulant medications.

To effectively answer the question of whether ADHD stimulant medication use may impact incidence of SUD, predictive modeling studies may be needed to help identify which people may be at increased risk for SUD outcomes. Further, studies included for KQ 2 of this review largely focused on people with cooccurring ADHD and stimulant use disorders, small sample sizes, and old formulations of stimulants. There is a need for sufficiently powered randomized trials of people with ADHD and SUD and modern formulations of stimulants, such as long-acting compounds. In addition, research on people with other substance use disorders, especially those frequently comorbid with ADHD (eg, alcohol, cannabis, benzodiazepine, and opioid use disorders) is needed. More research is needed to prepare VA providers not just for people diagnosed with ADHD as adults, but also for the growing population of people diagnosed in early childhood that have always depended on ADHD treatment as part of their standard health care. Finally, studies generally conducted follow-up over a long period of time (in 4 of 5 studies follow-up was >10 years) and there were limited data on short-term outcomes, such as those that may occur in the immediate months following stimulant initiation.

## CONCLUSIONS

Among people prescribed stimulants for ADHD, approximately 1 in 7 is newly diagnosed with SUD. However, the overall evidence does not indicate that stimulant medication treatment for ADHD increases the risk of SUD diagnoses. There are sparse longitudinal data on new onset AUD, or non-alcohol substance use disorders. Little is known about the risk of diversion or misuse among people prescribed stimulants for ADHD.

For people with co-occurring ADHD and SUD, there is no evidence of a difference in ADHD treatment adherence, substance use, SUD symptom change, or abstinence from SUD between those treated with stimulants and those receiving other forms of care. For the same comparison, there is insufficient evidence to assess ADHD symptom change, SUD treatment adherence, and medication misuse or diversion.

Longitudinal data or predictive modeling studies are needed to fill the evidence gap on ADHD medication diversion or misuse among people prescribed stimulants for ADHD. New comparative evidence is needed to assess the effects of stimulants on SUD treatment adherence, and medication misuse or diversion among people with co-occurring ADHD and SUD. Future studies should use a standardized set of measures to evaluate ADHD and SUD-related symptoms.