# RESULTS

## LITERATURE FLOW DIAGRAM

The literature flow diagram summarizes the results of the study selection process. A full list of excluded studies is provided in Appendix B.

Notes. We reviewed references from 15 applicable systematic reviews and/or meta-analyses; no meta-analysis included results that were fully applicable to this review.

Abbreviations. ADHD=attention-deficit/hyperactivity disorder; DSM=Diagnostic and Statistical Manual of Mental Disorders; KQ=key question; SUD=substance use disorder.

## OVERVIEW OF INCLUDED STUDIES

Of 6,419 unique records screened, 146 underwent full-text review. Upon reviewing these, 7 studies were eligible for KQ 1^63–69^ and 7 were eligible for KQ 2.^70–76^ The most common reasons for exclusion included outcomes not being reported in adult or majority adult samples (N = 18), studies not reporting outcomes by stimulant use status (N = 15), and studies not including longitudinal data (N = 10).

Table 2 shows the summary characteristics of the eligible studies. Appendix D presents design details and Appendix E presents baseline characteristics. Two studies used a similar set of data, specifically 1 study examined outcomes in an original cohort, and the second examined outcomes in these same probands along with qualifying siblings.^63,^ ^69^ Similarly, in a different set of publications, 1 examined outcomes from a RCT, and another examined outcomes in a subgroup of people within this study.^74,^ ^75^ Reporting the co-publications as separate studies, there were 6 RCTs, 4 NRCS, and 4 single-group studies. All 6 RCTs compared psychostimulant medications to placebo with cognitive behavioral therapy (CBT) or individual skills training targeted at substance use, and 1 of these studies also included a non-stimulant ADHD medication treatment arm. Most of the studies were conducted in the US (N = 9), followed by Denmark (N = 2), Sweden (N = 2), and Norway (N = 1). ADHD was defined using the DSM-IV-TR (N = 6), DSM III-R (later reassessed using the DSM-IV) (N = 2), ICD-10 codes (N = 2), Conners’ Adult ADHD self and observer rating scales (N = 1), by a regional expert committee (N = 1), or some combination of these (N = 2).

The studies evaluated a variety of interventions (Appendix F). Across both KQs, 10 studies explicitly mentioned methylphenidate as part of the stimulant treatment (either alone or in combination with other treatments, 2 studies included only mixed amphetamine salts,^74,^ ^75^ and 2 studies did not specify the medications included as part of the stimulant group.^69,^ ^70^

Table 2 Summary Characteristics of Eligible Studies

Characteristics | KQ1 (N = 7)^a^ | KQ2 (N = 7)^a^
Design
RCT (N = 6) | 0 | 6
NRCS (N = 4) | 3 | 1
Single group (N = 4) | 4 | 0
Risk of Bias
Low (N = 5) | 3 | 2
Moderate (N = 8) | 4 | 4
High (N = 1) | 0 | 1
Countries
United States (N = 9) | 3 | 6
Denmark (N = 2) | 2 | 0
Norway (N = 1) | 1 | 0
Sweden (N = 2) | 1 | 1
Stimulant Treatment (Number of Studies That Included the Following)
Stimulants (any/multiple/not specified) (N = 5) | 4 | 1
Methylphenidate only (N = 7) | 3 | 4
Mixed amphetamine salts (N = 2) | 0 | 2
Stimulant plus another active pharmaceutical for ADHD (N = 1) | 1 | 0
Non-stimulant pharmaceutical comparison, no treatment, or placebo (N = 10) | 3 | 7^b,c^
Outcomes (Number of Studies That Included the Following) ^d^
Incident SUD (KQ1) (N = 7) | 7 | -
Diversion or Misuse Outcomes (N = 2) | 1 | 1
ADHD Treatment Adherence (N = 4) | 0 | 4
SUD Treatment Adherence (N = 2) | 0 | 2
ADHD Symptom Change (N = 5) | 0 | 5
SUD Symptom Change (N = 2) | 0 | 2
Abstinence (KQ2) (N = 5) | - | 5
Substance Use (KQ2) (N = 5) | - | 5
Other Symptom Change (N = 1) | 0 | 1
Adverse Events (N = 4) | 0 | 4

Notes.

a In 2 co-publications, 1 study examined outcomes in an original cohort, and the second examined outcomes in these same probands along with qualifying siblings;

b Six of these included either CBT or individual skills training for SUD in all groups;

c Some studies included multiple comparison groups, but each study was only counted once in this table;

d Studies may have reported multiple results for a given outcome category, but each study was only counted once per outcome category in this table.

Abbreviations. ADHD=attention-deficit/hyperactivity disorder; KQ=key question; N=number; NRCS=non-randomized comparative study; SUD=substance use disorder.

## EFFECT OF STIMULANTS ON THE INCIDENCE OF SUD, MISUSE, AND DIVERSION IN PEOPLE WITH ADHD WITHOUT SUD AT BASELINE

Seven studies (3 NRCS and 4 single group) enrolling participants between 1970 and 2010 (3 studies did not report dates of enrollment) included 58,077 people.^63–69^ Wilens et al 2006 added data of siblings to the participants included in Biederman et al 2008 (treated as 2 separate publications).^63,^ ^69^ Three studies were conducted in the US, 2 in Denmark, 1 in Norway, and 1 in Sweden. Three studies included a comparator group of people either untreated for ADHD, treated with non-stimulant ADHD medications, or some combination of these groups.^63,64,67^ Methylphenidate was the most commonly used stimulant (N = 6), followed by dexamphetamine (N = 2), amphetamine products (N = 2), and pemoline (N = 1). One study did not specify the type of stimulant used.^69^ Only 2 studies reported stimulant dosage (mean 41.7 mg methylphenidate;^66^ mean maximum dose of 58.7 mg methylphenidate^68^). Stimulant treatment duration ranged from approximately 2 years to up to 6 years in 4 studies that reported this information.^63,^ ^66–68^ In 5 of these studies, length of follow-up ranged from 3 to 19 years, with 4 of these having 10 or more years of follow-up. Two studies did not report length of follow-up. Two studies reported loss to follow-up (15% and 20%),^63,^ ^66^ and 5 studies did not report any information on attrition.

In all 7 studies, people were without SUD at baseline. At baseline, the age of people was between 6 and 46 years old. For 4 studies that included people diagnosed with ADHD in childhood, 2 studies reported a mean age at baseline of 10.5 and 15.2 years^63,^ ^67^ and 2 reported the age at baseline ranged from 6 to 17.^66,^ ^69^ In the single study that enrolled only adults, the mean age was 28.4.^68^ In the 1 study that included adults and children at baseline, approximately 75% were age 8–25, 13.3% were aged 26–35, and 11.4% were 36–46 years old.^64^ Only 2 studies reported mean age at treatment initiation (both 8 years of age).^63,^ ^66^ Three studies reported that samples were majority White (100% in all),^63,66,69^ and the remaining studies did not report information about race/ethnicity. All studies included mostly males (range = 65.4%–100%).

The 7 studies reported various measures of SUD outcomes. Two studies reported SUD, and 3 studies reported AUD separately from other substances or SUD. Finally, 2 studies reported the use of drugs separately from AUD or SUD (ie, non-alcohol substance use or stimulant use disorders). When studies reported SUD, AUD, or non-alcohol substance use disorders, it was not always clear whether these were mutually exclusive. As noted above, Appendix G reports the categorization of substance use outcomes in each study.

Three studies (1 NRCS and 2 single group) were rated moderate risk of bias because they did not clearly report whether outcome assessors were masked and had an additional concern (high attrition, inclusion of only people with high ADHD severity that may not be representative of the average ADHD population, and unclear reporting of comparator representativeness) (Appendix C).^64,65,69^ One single group study was rated as moderate risk of bis for having unclear reporting.^66^ Three studies (2 NRCS and 1 single group) had no concerns (ie, low risk of bias).^63,67,68^

In summary (Table 3), 1 in 7 (14%) people prescribed stimulants for ADHD is newly diagnosed with SUD, though estimates varied drastically across studies. There were insufficient data to pool estimates for the incidence of AUD or non-alcohol substance use or stimulant use disorders in those with ADHD prescribed stimulant medications. One small single-group study assessed diversion (11% of people) or misuse (10% to 31% depending on definition) among people prescribed stimulants for ADHD. There was no evidence of a difference for SUD for people with ADHD prescribed stimulant medications compared to those who were not prescribed stimulant medications (low confidence). Studies provide insufficient evidence (no conclusion) for AUD and non-alcohol substance use or stimulant use disorders for people with ADHD prescribed stimulant medications compared to those who did not. Comparative studies did not assess diversion or misuse.

Table 3 Summary of Findings for Incidence of SUD

Outcome | Studies (People); Design | Methodological Limitations | Indirectness | Imprecision | Inconsistency | Other Issues | Summary | Overall Confidence
Incidence of Stimulants on SUD and Diversion/Misuse ^a^
SUD | 5 (12823); 1 NRCS and 4 Single group | Moderate^b^ | Direct | Imprecise^c^ | Inconsistent^d^ | None | Pooled proportion = 0.14, 95% CI (0.02, 0.35) | (Not graded)^e^
AUD | 2 (384); 2 Single group | Moderate^f^ | Direct | Imprecise^c^ | Inconsistent^d^ | None | No conclusion; - AUD = 0.05 (0.03, 0.09) and 0.28 (0.21, 0.35) | (Not graded)^e^
Non-alcohol substance use or stimulant use disorder | 1 (176); 1 Single group | Moderate^g^ | Direct | N/A^a^ | N/A^a^ | Single study | No conclusion; - Non-alcohol disorders = 0.37(0.30, 0.45);; - Stimulant disorders = 0.24 (0.18, 0.31) | (Not graded)^e^
Diversion or misuse | 1 (55); Single group | Moderate^h^ | Direct | N/A^a^ | N/A^a^ | Single study | No conclusion; - 11% reported diversion, 22% reported misusing medications and 31% reported using ADHD medication with drugs or alcohol. | (Not graded)^e^
Effect of Stimulants on Incidence of SUD and Diversion/Misuse ^i^
SUD | 2 (57,455); NRCS | Moderate^j^ | Direct | Precise | Inconsistent^k^ | None | No evidence of a difference stimulant use; - 2 studies found no significant difference in SUD.; - 1 found significantly more incident SUD in a mixed medicine group. | Low
AUD | 1 (131); NRCS | Low | Direct | N/A^a^ | N/A^a^ | Single study | No conclusion | Insufficient evidence
Non-alcohol substance use or stimulant use disorder | 1 (131); NRCS | Low | Direct | N/A^a^ | N/A^a^ | Single study | No conclusion | Insufficient evidence
Diversion or misuse | | NA | NA | NA | NA | NA | NA | No evidence

Notes.

a Informed by single group data;

b Three studies had moderate risk (concerns about cohort representativeness, lack of clear reporting, high attrition and unclear blinding of outcome assessor);

c Wide confidence interval for pooled estimate;

d Wide variation in estimates;

e See Methods: we assessed the various GRADE domains to communicate information about the characteristics of the studies but did not provide an overall rating for how the incidence estimates compare with a reference incidence (eg, the corresponding incidence in the general population);

f Two had moderate risk of bias (concerns about cohort representativeness, lack of clear reporting, and unclear blinding of outcome assessor);

g One had moderate risk of bias (unclear reporting);

h Moderate risk of bias due to high attrition and unclear blinding of outcome assessor;

i Informed by comparative data;

j One study had moderate risk of bias (unclear blinding of outcome assessor and unclear comparator representativeness), and 1 had no concerns (low risk);

k Variation in estimate direction.

Abbreviations. N/A=not applicable; NRCS=non-randomized comparative study; SUD=substance use disorder.

### Incident SUD

Five studies found that the proportion of people with a new SUD diagnosis in people prescribed stimulants for ADHD ranged between 0.00 to 0.53 (pooled proportion = 0.14, 95% CI [0.02, 0.35]; Figure 1).^65–69^ There was high heterogeneity across the studies with differences in baseline age and follow-up duration. The baseline age was between 6 and 17 years in 2 studies reporting ≥45% of people developed a SUD diagnosis following a prescription of stimulant medications. In 4 studies reporting ≤12% of people with SUD among those prescribed stimulants, mean baseline age was 15 years in 2 studies, 28 in 1 study, and was not reported in the fourth study. One study reported 0 cases of new SUD diagnoses among those prescribed stimulants. Two studies found the proportion of people with a new AUD after being prescribed psychostimulants for ADHD was 0.05 and 0.28 (Figure 1).^65,66^ Two studies did not report length of follow-up and 1 study did not report age at baseline.

One study found that among those prescribed stimulants for ADHD (mean age at follow-up 25 years), 37% of people had a non-alcohol disorder and 24% had a stimulant use disorder.^66^

Figure 1 Incidence of SUD Among People With ADHD Treated With Stimulant Medications

Notes. ^a^Two groups from the Steinhausen 2014 study were included, numbers include data for people without SUD at the time of medication onset (across all study groups, 97 people had an SUD diagnosis before the beginning of the prescription register, so their medication status was unknown); ^b^Estimates were not pooled since data were only from 2 studies; ^c^Estimates were not pooled since data were only from 1 study.

Abbreviations. depend=dependence; mo=month; med=medication; MPH=methylphenidate; n/N=number; NR=not reported; prop=proportion; SD=standard deviation; stim=stimulants; y=years.

### Diversion/Misuse

One study reported on prescription stimulant diversion or misuse over 10 years of follow-up among adults with ADHD diagnoses and no history of SUD at baseline.^69^ Importantly, this was a small study (N = 55), it included adolescents and college-age adults, and also likely included older stimulant medications. In this study, 11% of the people reported they sold their medication, 22% took too much of their prescribed medication or misused it in some way, and 10% got high on their medication. The study also reported that 16% of people reported skipping their medication to use alcohol or drugs, 31% used their medications with alcohol, and 5% experienced a reaction when using their ADHD medication and alcohol or drugs.

### Effect of Stimulants on Incident SUD

Three NRCS reported new SUD diagnoses among adults with ADHD who had been prescribed stimulant medications during their lives compared to those were never prescribed stimulants (Appendix H).^63,64,67^ Because of differences in substances assessed (eg, general substance use, general drug, alcohol), and effect measures, we did not pool these data. Figure 2 provides a non-pooled visualization of the outcomes from the comparative studies for SUD.

#### SUD

Two NRCS found no significant difference in incident SUD diagnoses between people with ADHD prescribed stimulant medications compared to those with ADHD who were not prescribed stimulants (Figure 2).^64,^ ^67^ One NRCS found no significant difference in new SUD diagnoses over 3 years between people with ADHD prescribed stimulants versus those with ADHD not prescribed stimulants (aHR = 0.97, 95% CI [0.78, 1.20]).^64^ Another NRCS followed people (~15 years) with ADHD prescribed various medications (eg, methylphenidate only, antidepressants only, antipsychotics only) and people with ADHD who had not received medications.^67^ This study found no significant difference in incident SUD between the methylphenidate-only group compared to those who had not received medications (aHR = 0.92, 95% CI [0.74, 1.15]). The same NRCS found significantly more incident SUD diagnoses for people prescribed mixed medications (where the majority included stimulants plus some other ADHD medication) compared to those who had not received medications (aHR = 1.48, 95% CI [1.31, 1.69]).^67^

Figure 2 Incident SUD Diagnoses Among People With ADHD Prescribed Stimulant Medications versus People With ADHD Not Prescribed Stimulants

Notes. ^a^Adjusted for sex, age, civil status, employment, living in metropolitan area, income psychiatric diagnosis, and criminal convictions; ^b^Two groups from the Steinhausen 2014 study were included, numbers include data for people without SUD at the time of medication onset (across all study groups, 97 people had an SUD diagnosis before the beginning of the prescription register, so their medication status was unknown); ^c^Adjusted for mood disorder, anxiety disorder, personality disorder, conduct disorder, hyperkinetic disorder unspecified, autism spectrum disorder, disturbance of activity and attention, and age at diagnosis.

Abbreviations. aHR=adjusted hazard ratio; DSM=Diagnostic and Statistical Manual of Mental Disorders; ICD=International Classification of Disease; med=medication; MPH=methylphenidate; n/N=number; NR=not reported; y=year.

#### Alcohol Use Disorders

One NRCS found no significant difference in alcohol abuse and alcohol dependence diagnoses over 10 years between those prescribed stimulants at some time in their lives compared to those who never took a stimulant (alcohol abuse aHR = 1.1, 95% CI [0.6, 2.1] and alcohol dependence (aHR = 1.0, 95% CI [0.5, 2.4]).^63^ In this study, it was unclear whether the same people were counted in the measure of abuse and dependence.

#### Non-Alcohol Substance Use or Stimulant Use Disorder

One NRCS reported no significant differences in drug abuse (aHR= 1.6, 95% CI [0.8, 3.2]) or drug dependence (aHR= 1.0, 95% CI [0.4, 2.6]) diagnoses over 10 years between people who were ever prescribed stimulants in their lifetime compared to those never prescribed stimulants.^63^ It was unclear whether the same participants were included in both outcomes.

### Diversion/Misuse

No comparative study reported data on diversion or misuse.

## EFFECT OF STIMULANTS ON ADHD AND SUD SYMPTOM AND TREATMENT OUTCOMES IN PEOPLE WITH CO-OCCURRING ADHD AND SUD

Seven studies (6 RCTS and 1 NRCS) enrolling participants between 1998 and 2020 (2 studies did not report dates) analyzed 662 people. Notzon 2016 was a subset of the Levin 2015 study population that had used marijuana within the 30 days prior to enrollment (treated as 2 separate publications).^74,^ ^75^ Study inclusion and exclusion criteria varied. The studies included people with a comorbid cocaine or amphetamine use disorder (N = 5) and people receiving methadone treatment for opioid use disorder (N = 1) or SUD (N = 1). Six studies were conducted in the US^70,^ ^72–76^ and 1 in Sweden.^71^ Four RCTs compared methylphenidate (dose range = 40–90 mg/day) to placebo,^71,72,74,76^ and 1 study also included a third comparison group of bupropion (maximum dose of 400 mg/day).^73^ Two RCTs compared extended-release mixed amphetamine salts (60 and/or 80 mg daily) to placebo.^74,^ ^75^ Importantly, in the 6 RCTs all groups also received either cognitive behavioral therapy (CBT) or individual skills training targeted at substance use during the study. One NRCS compared any stimulant (dose not reported) to non-stimulant treatment or those receiving no treatment.^70^ Treatment duration in the RCTs ranged from 12–14 weeks^71–76^ and treatment duration in the NRCS was estimated to be approximately 2 years.^70^ In the RCTs, the length of follow-up ranged from 12–14 weeks^71–76^ and loss to follow-up ranged from 25%–56.6% in the stimulant treatment groups and 24.2%–54.7%in the comparison groups.^72–74,^ ^76^ Loss to follow-up was not reported in the NRCS.^70^

Overall, mean age of people at baseline ranged from 37–40.4 years. Most participants (57%–89.6%) were male. Six studies reported race/ethnicity information of samples with the proportion of people who were White ranged from 39.8–89.6%.

Four RCTs did not blind outcome assessors and had incomplete outcome data with high dropout rates (ie, medium risk of bias). The remaining 2 RCTs had no methodological concerns (ie, low risk of bias). The 1 NRCS reported results from a crude analysis with no clear reporting of eligibility between comparison groups, unclear reporting for some outcomes, and concerns of incomplete outcome data (ie, high risk of bias).

In summary (Table 4), there was no evidence of differences in ADHD treatment adherence, substance use, SUD symptom change, or abstinence from SUD in people with co-occurring ADHD and SUD prescribed stimulants versus their counterparts not prescribed stimulants (low confidence for all). Studies provide insufficient evidence (no conclusion) for ADHD symptom change, SUD treatment adherence, medication misuse/diversion, and measures of depression and anxiety. There was no evidence of a difference in various measures of adverse events (strength of evidence not assessed).

Table 4 Summary of Findings for Stimulants in People With Co-Occurring ADHD and SUD

Outcome | Studies (People); Design | Methodological Limitations | Indirectness | Imprecision | Inconsistency | Other Issues | Summary | Overall Confidence
ADHD symptom change | 5 (402); RCT | Moderate^a^ | Direct | Imprecise^b^ | Inconsistent^c^ | None | No conclusion^d^; - Three studies reported no significant difference, 1 study reported a significant improvement in the stimulant group and 1 study reported mixed findings. | Insufficient evidence
ADHD treatment adherence | 4 (354); RCT | Moderate^e^ | Direct | Imprecise^f^ | Consistent | None | No evidence of a difference in ADHD treatment adherence for stimulants compared to placebo; - 3 of 4 studies found no significant difference in a measure of treatment adherence. | Low
Substance use | 5 (333); RCT | Moderate^a^ | Direct | Precise | Inconsistent^c^ | None | No evidence of a difference in substance use for stimulants compared to placebo; - Mixed results for opiate, alcohol and cannabis use.; - No difference in illicit amphetamine, cocaine, “other” or “any” drug use and time to relapse. | Low
SUD symptom change | 2 (130); RCT | Moderate^g^ | Direct | Precise | Inconsistent^h^ | None | No evidence of a difference in SUD symptom change. | Low
SUD treatment adherence | 2 (329); NCRS, RCT | High^i^ | Direct | Precise | Inconsistent^c^ | | No conclusion; - One study reported significantly longer SUD treatment retention in the stimulant group.; - One study reported no significant differences in number of completed CBT sessions. | Insufficient evidence
Abstinence | 5 (402); RCT | Moderate^a^ | Direct | Precise | Inconsistent^j^ | None | No evidence of a difference in abstinence outcomes; - Four of 5 studies found no significant differences in abstinence outcomes. | Low
Medication misuse/diversion | 1 (98); RCT | Moderate^k^ | Direct | N/A^l^ | N/A^l^ | Small single study | No conclusion; - One study found no reports of misuse or diversion in any patients. | Insufficient evidence
Other | 1 (24); RCT | Low | Indirect^m^ | N/A^l^ | N/A^l^ | Small single study | No conclusion; - One study found no significant differences in Beck Depression Inventory, Beck Anxiety Inventory, or Stroop Test scores between stimulant and comparison groups | Insufficient evidence

Notes.

a Three studies had moderate risk of bias (high attrition, unclear blinding of outcome assessor, unclear allocation concealment, and/or unclear random sequence generation) and 2 studies had low risk;

b Wide confidence intervals in 2 studies;

c Studies used a variety of measures, and direction of results varied across studies;

d One study also included a bupropion arm, but overall evidence was assessed for stimulants compared to any other treatments;

e Three studies had moderate risk of bias (high attrition, unclear blinding of outcome assessor, unclear allocation concealment, and/or unclear random sequence generation) and 1 study had low risk;

f One study had a wide confidence interval and another did not report any measures of variability;

g One study had moderate risk of bias (high attrition, unclear blinding of outcome assessor, allocation concealment, and random sequence generation) and 1 study had low risk;

h Different assessments used;

i One study had high risk of bias (an NRCS with unclear reporting, unclear eligibility criteria, outcomes not fully defined, and no adjustment for confounding) and 1 study had moderate risk of bias (high attrition);

j Directions of results varied across studies;

k Study had moderate risk of bias (high attrition, unclear blinding of outcome assessor, allocation concealment, and random sequence generation);

l Single study;

m Assessments did not directly align with key question.

Abbreviations. ADHD=attention-deficit/hyperactivity disorder; CBT=cognitive behavioral therapy; NRCS=non-randomized comparative study; SUD=substance use disorder.

### ADHD Symptom Change

#### Categorical Measures of Symptom Change

Four RCTs reported 6 different categorical measures of ADHD symptom change (Appendix H and Appendix I).^72–74,^ ^76^ Three of these RCTs were published by the same authorship group, which accounted for 86% of the ADHD symptom change outcomes.^72–74^

Three RCTs from the same author group reported no significant difference in the proportion of people who had improvement on the Clinical Global Improvement (CGI) scale from baseline to follow-up (12 or 14 weeks) between people who received either methylphenidate or mixed amphetamine salts with CBT compared to placebo with CBT (pooled OR = 1.27, 95% CI [0.32, 5.09]; Figure 3).^72–74^ One of these RCTs also found no significant difference in change on the CGI from baseline to follow-up between people who received either methylphenidate with CBT compared to bupropion with CBT (OR = 0.53, 95% CI [0.17, 1.69]).^73^

Two RCTs found no significant difference in symptom change (≥30% reduction in Adult ADHD Rating Scale [AARS]) between those in the methylphenidate with CBT group compared to those taking a placebo with CBT during the 12 and 14 week trials (OR = 0.63, 95% CI [0.23, 1.71] and 0.74 [0.34, 1.59]).^72,^ ^73^ These 2 RCTs also found no significant difference in people who had a combined improvement of ≥30% reduction in AARS and CGI rating of <3 for people who received methylphenidate with CBT compared to placebo with CBT (OR = 0.38, 95% CI [ 0.09, 1.64] and 1.10 [0.47, 2.53]).^72,^ ^73^ In addition, 1 of these RCTs also compared people taking methylphenidate with CBT to those assigned to receive bupropion. This RCT found no significant differences in people with >30% reduction in AARS (OR = 0.56, 95% CI [0.2, 1.51]) or those with a combined CGI <3 and ≥30% reduction in AARS (OR = 0.58, 95% CI [0.13, 2.66]) between the methylphenidate with CBT and bupropion with CBT groups.^73^

One RCT reported no significant difference in symptom change (≥30% reduction in the Targeted Adult Attention-Deficit/Hyperactivity Disorder [TAADDS]) between people who received methylphenidate with CBT compared to placebo with CBT over 14 weeks (OR = 1.66, 95% CI [0.74, 3.75]).^72^

One RCT found a significant improvement in symptoms, defined as a >30% reduction in Adult ADHD Investigator Symptom Rating Scale (AISRS) score from baseline to 14 week follow-up, in the mixed amphetamine salts with CBT group compared to placebo with CBT group (OR = 3.00, 95% CI [1.40, 6.44]).^74^

Another RCT reported significantly more people had a moderate improvement (defined as 1 or 2 points on 7-point scale) at 12 week follow-up based on either physician (OR = 12.59, 95% CI [3.21, 49.41]) or patient ratings (OR = 3.73, 95% CI [1.11, 12.55]) for those receiving methylphenidate with CBT compared to placebo with CBT.^76^

Figure 3 ADHD Symptom Change (Categorical Measures)

Notes. ^a^Study included both a placebo and bupropion comparison group; ^b^Data were not pooled due to use of active comparator.

Abbreviations. AARS=Adult ADHD Rating Scale; AISRS=Adult ADHD Investigator Symptom Rating Scale; amph=amphetamine salts; CBT=cognitive behavioral therapy; CGI=Clinical Global Improvement Scale; MPH=methylphenidate; n/N=number; OR=odds ratio; TAADDS=Targeted Adult Attention Deficit Disorder Scale; w=weeks.

#### Continuous Measures of Symptom Change

Three RCTs reported ADHD symptom change using continuous measures.^71,74,76^ One RCT found significant improvements at 14 week follow-up on the CGI as a continuous measure in those taking mixed amphetamine salts with CBT compared to those taking placebo with CBT (MD = 0.64, 95% CI [0.19, 1.09]).^74^ The same study also reported significant improvement on the CGI as a categorical measure (described above). The same RCT also reported significant improvements in changes on AISRS scores (MD = 9.41, 95% CI [4.75, 14.07]), Conners Adult ADHD Rating Scales (CAARS) hyperactive scale scores (MD = 8.88, 95% CI [3.33, 14.43]), CAARS inattentive scale scores (MD = 10.87, 95% CI [5.34, 16.40]), and total CAARS scores (MD =11.09, 95% CI [5.48, 16.70]) for people randomized to mixed amphetamine salts with CBT compared to placebo with CBT.^74^ Another RCT found no significant differences in the CAARS self-rated scale (MD = −10.6, 95% CI [−3.65, 24.85]) or observer-rated scale (MD = −0.10, 95% CI [−11.01, 10.81]) between those who received methylphenidate with skills training compared to placebo with skills training at 13 weeks follow-up.^71^

One RCT found no significant differences in the number of inattentive (MD = −0.70, 95% CI [−2.39, 0.99]) or hyperactive (MD = −1.36, 95% CI [−3.07, 0.35]) symptoms at 12 week follow-up between people who received methylphenidate with CBT compared to placebo with CBT.^76^

### ADHD Treatment Adherence

Three of 4 RCTs found no significant difference in ADHD treatment adherence. One RCT reported lower treatment compliance (based on positive urine fluorescence) over 12 weeks in the methylphenidate with CBT group compared to placebo with CBT and bupropion with CBT groups (77% vs 83% vs 91%, overall p = 0.40).^73^ One RCT reported no significant difference in the proportion of urine samples with positive fluorescence for ADHD medications in people taking methylphenidate with CBT compared to placebo with CBT over 14 weeks (MD = 0.02 [−0.05, 0.15]).^72^ Another RCT reported no significant difference in positive fluorescence between those taking mixed amphetamine salts with CBT compared to placebo with CBT over 14 weeks (effect size not reported, p = 0.57).^74^ An RCT reported no significant difference in treatment retention over 13 weeks between people randomized to methylphenidate plus skills training or placebo plus skills training (OR = 3.65, 95% CI [ 0.53, 25.01]).^71^

### Substance Use

#### Categorical Measures of Substance Use

Three RCTs examined either cannabis, amphetamine, or opioid SUD-related outcomes in people with ADHD and SUD at baseline using categorical measures (Figure 4). One RCT, which included people with comorbid ADHD and amphetamine dependence, reported significantly greater odds of having a THC-positive urine sample over 14 weeks among people receiving methylphenidate with CBT compared to placebo with CBT (OR = 2.56, 95% CI [1.85, 3.57]).^72^ Conversely, another 14 week RCT limited to people who reported smoking cannabis at baseline reported significantly lower cannabis smoking among people assigned to methylphenidate plus CBT compared to placebo plus CBT (OR = 0.20, 95% CI [0.05, 0.75]).^75^

One RCT of people with comorbid ADHD and amphetamine dependence reported no significant difference in illicit amphetamine use between methylphenidate with CBT and placebo with CBT groups at 14 week follow-up (OR = 0.24, 95% CI [0.01, 5.52]).^72^

Two RCTs reported on opioid use between methylphenidate with CBT and placebo with CBT. One 12-week RCT included people with both adult ADHD and cocaine dependence/abuse and who were also receiving methadone treatment for opioid use disorder. This RCT found a lower proportion of weeks people tested positive for opioids for those who received methylphenidate with CBT compared to placebo with CBT (OR = 0.74, 95% CI [0.55, 0.99]). The same study found a lower (not statistically significant) proportion of weeks people tested positive for opioids between those who received methylphenidate with CBT compared to bupropion (OR = 0.84, 95% CI[0.62, 1.13]).^73^ Another RCT (14 weeks) in people with comorbid ADHD and cocaine dependence reported no significant differences in illicit opioid use during the study between methylphenidate with CBT compared to placebo with CBT (OR = 1.00, 95% CI [0.06, 16.42]).^72^

Figure 4 Substance Use (Categorical Measures)

Notes. ^a^Study included both a placebo and bupropion comparison group.

Abbreviations. amph=amphetamine salts; CBT=cognitive behavioral therapy; MPH=methylphenidate; n/N=number; NR=not reported; OR=odds ratio; prob=probability; THC=tetrahydrocannabinol; w/wks=weeks.

#### Continuous Measures of Substance Use

Four RCTs reported alcohol, cannabis, cocaine, amphetamine, or other SUD outcomes using continuous measures in people with ADHD and SUD at baseline. One RCT of people with comorbid ADHD and amphetamine dependence reported significantly fewer days of alcohol use of <60 g/day for those receiving methylphenidate with skills training compared to placebo with skills training at 13 weeks follow-up (MD = −11.0 days, 95% CI [−20.89, −1.11]). The same trial reported no significant difference in the mean number of days people used alcohol >60 g/day between groups (MD = −3.80 days, 95% CI [−12.18, 4.58].^71^

One RCT reported a higher mean level of THC in urine samples in the methylphenidate with CBT group compared to placebo with CBT group at 14 weeks follow-up (MD = 239.00 ng/ml, 95% CI [216.54, 261.46]).^72^

Three RCTs reported cocaine use between those receiving methylphenidate with CBT compared to placebo with CBT. An RCT of people receiving methadone treatment for opioid use disorder with both adult ADHD and cocaine dependence/abuse reported no significant difference in the proportion of weeks (over 12 weeks) people tested positive for cocaine between methylphenidate with CBT and placebo with CBT (MD = 0.00, 95% CI [−0.19, 0.19]).^73^ Another RCT of people with comorbid ADHD and amphetamine dependence also reported no significant difference in the proportion of weeks (over 14 weeks) that were cocaine positive between those receiving methylphenidate with CBT and placebo with CBT (MD = 0.03, 95% CI [−0.05, 0.15]).^72^ One RCT found that among those with ADHD seeking treatment for cocaine use disorder, there were no significant differences in the proportion of urine samples that tested positive for cocaine over the 12 week study between methylphenidate with CBT and placebo with CBT groups (MD = 0.08, 95% CI −0.16, 0.32]).^76^

One RCT of people with comorbid ADHD and amphetamine dependence reported no significant difference in days of amphetamine use over 13 weeks between methylphenidate with skills training and placebo with skills training (urine toxicology MD = 2.00 days, 95% CI [−5.04, 9.04] and self-report MD = 0.50 days, 95% CI [−5.07, 6.07]).^71^

Two RCTs reported on other substance use outcomes. One RCT of people with comorbid ADHD and amphetamine dependence reported no significant difference in days of other illicit drug use between methylphenidate with skills training and placebo with skills training over the 13 week (urine toxicology MD = 0.60 days, 95% CI [−2.49, 3.69] and self-report (MD = −4.10 days, 95% CI [−8.33, 0.13]).^71^ This same study reported a similar time to relapse in the methylphenidate with CBT group and placebo with CBT group (mean = 3.33 [2.2–5.4] days vs 3.80 [1.8–4.9] days, p = NS). Another RCT that included people receiving methadone treatment for opioid use disorder with both adult ADHD and cocaine dependence/abuse reported no significant difference between groups in the proportion of positive weeks for any drug during the 12 week study (MD = 0.03, 95% CI [−0.01, 0.07]).^73^

One RCT that included people receiving methadone treatment for opioid use disorder with both adult ADHD and cocaine dependence/abuse reported on substance use outcomes between those receiving methylphenidate and those receiving bupropion. This RCT found no significant differences in the mean proportion of positive weeks (based on urine) for cocaine (MD = −0.05 weeks, 95% CI [−0.23, 0.13]) or any drug (MD = 0.01, 95% CI [−0.03, 0.05]) during the 12-week study.^73^

### SUD Symptom Change

Two RCTs reported no significant difference in SUD symptom change between methylphenidate with CBT compared to placebo with CBT. One RCT found no significant difference in the proportion of people achieving a CGI cocaine improvement score of <3 in people receiving methylphenidate with CBT compared to placebo with CBT at 14 week follow-up (OR = 1.58, 95% CI [0.73, 3.42]).^72^ One RCT reported no significant difference in substance craving based on a 7-point visual analog scale between methylphenidate with skills training and placebo with skills training groups at 13 weeks follow-up (MD = −0.5, 95% CI [−1.83, 0.83]).^71^

### SUD Treatment Adherence

One RCT and 1 NRCS reported SUD treatment adherence outcomes. The NRCS reported significantly longer SUD treatment retention for people with comorbid ADHD and SUD who received stimulant medication within 90 days of admission to an outpatient SUD program compared to their counterparts who did not receive stimulants (aHR = 0.59, 95% CI [0.40, 0.87]).^70^ One RCT reported no significant difference over 14 weeks in the number of CBT sessions attended between those assigned to receive mixed amphetamine salts with CBT compared to placebo with CBT (MD = 1.19, 95% CI [(−0.36, 2.74]).^74^

### Abstinence

#### Categorical Measures

Two of 3 RCTs (all from the same author group) reported no significant difference in a categorical measure of abstinence from substance use (Figure 5). One RCT (12 weeks) reported no significant differences in the odds of ≥2 consecutive weeks of abstinence for all participants (OR = 0.58, 95% CI [0.13, 2.66]) or a subgroup of current cocaine abusing/dependent people (OR = 1.09, 95% CI [0.16, 7.59]) for people receiving methylphenidate with CBT compared to placebo with CBT.^73^ A 14-week RCT reported no significant difference in the odds of ≥2 consecutive weeks of abstinence between methylphenidate with CBT and placebo with CBT groups (OR = 0.87, 95% CI [0.31, 2.46]).^72^ Another 14-week RCT reported significantly more people had ≥3 consecutive weeks of abstinence in the mixed amphetamine salts with CBT group compared placebo with CBT group (aOR = 8.74, 95% CI [1.78, 42.97]).^74^ One 12-week RCT reported no significant difference in ≥2 consecutive weeks of abstinence for people randomized to methylphenidate with CBT or bupropion with CBT (OR = 1.60, 95% CI [0.25, 10.29]). The same RCT found no significant difference in ≥2 consecutive weeks of abstinence in a sub-analysis of current cocaine abusing/dependent people in the methylphenidate with CBT compared to placebo with CBT (OR = 1.45, 95% CI [0.18, 11.94]).^73^

Figure 5 Abstinence (Categorical Measures)

Notes. Outcome defined as abstinence from substance use for ≥2 consecutive weeks. ^a^Study included both a placebo and bupropion comparison group; ^b^Adjusted estimate (covariates not reported).

Abbreviations. amph=amphetamine salts; CBT=cognitive behavioral therapy; MPH=methylphenidate; n/N=number; OR=odds ratio; w/wks=weeks.

#### Continuous Measures

Two RCTs reported no significant differences in the longest period of abstinence between stimulant and placebo groups over 12 and 13 weeks (MD = 0.00 days, 95% CI [−3.42, 3.42] and 0.70, 95% CI [−2.01, 3.41]).^71,^ ^76^

### Medication Misuse or Diversion

One RCT found no instances of ADHD medication diversion or of medications making people subjectively high or euphoric for the methylphenidate with CBT, bupropion with CBT, or placebo with CBT.^73^

### Other Symptom Change

One RCT reported no significant differences in change in Beck Anxiety Inventory (MD = −3.9, 95% CI [−8.45, 0.65]) or Stroop test score (MD = 4.40, 95% CI [−9.92, 18.72]) at 13 week follow-up between methylphenidate with skills training and placebo with skills training.^71^ This study reported no significant differences in change in the Beck Depression Inventory scores in the article (p = 0.138), though the MD calculated from the data provided in the study indicated a significant reduction in the BDI scores for those taking methylphenidate compared to placebo (MD = −7.30, 95% CI [−14.18, −0.42]).

### Side Effects and Adverse Events

Four RCTs reported on side effects or adverse events. Two RCTs reported a large but not statistically significant increase in the proportion of people who needed their medication doses lowered due to side effects between methylphenidate with CBT and placebo with CBT groups (OR = 4.24, 95% CI [0.46, 39.31] and OR = 3.83, 95% CI [0.67, 21.84]).^72,^ ^76^ Another RCT reported a large but not statistically significant difference in people who needed their treatment dosages lowered between methylphenidate with CBT and bupropion with CBT arms (OR = 3.31, 95% CI [0.33, 33.63]).^73^ Finally, 1 RCT reported significantly fewer people in the mixed amphetamine salts with CBT group tolerated their assigned treatment dose compared to those in the placebo with CBT group (OR = 0.27, 95% CI [0.09, 0.77]).^74^

Three RCTs reported no significant differences in the proportion of people who discontinued their medication or ended the trial due to adverse events between treatment and placebo arms (OR range = 0.50–1.65, all non-significant).^72–74^

One RCT reported more people experienced insomnia or trouble sleeping in those who received methylphenidate with CBT compared to placebo with CBT (OR = 3.46, 95% CI [1.05, 11.34]).^76^ However, 2 other RCTs reported no significant difference in insomnia between stimulant and placebo groups (OR = 7.1, 95% CI [0.89, 56.56]; OR = 4.85, 95% CI [0.57, 41.22]).^72,^ ^74^

Four studies reported no significant difference in other side effects including fatigue, anxiety, depression or sadness, headache, irritability or agitation, gastrointestinal or digestive upset (such as vomiting or diarrhea), chest pain, palpitations or racing heart, changes in appetite, or other side effects between treatment arms. A full list of reported side effects can be found in Appendix J.