# METHODS

## TOPIC DEVELOPMENT

We worked with representatives from the OMHSP and our technical expert panel (TEP) to refine the scope and develop key questions (KQ). We focused on studies that reported incident outcomes of SUD (including alcohol use disorder or alcohol abuse) or medication misuse or diversions (KQ 1), and those that examined the effect of stimulant use in people with both ADHD and SUD (KQ 2). We excluded studies that did not report outcomes in adulthood (≥18 years of age) and studies that only evaluated tobacco or caffeine use as an SUD.

## KEY QUESTIONS AND PROTOCOL REGISTRATION

The following key questions were the focus of this review:

Key Question 1 | Among adults diagnosed with ADHD and prescribed psychostimulant medications, what is the incidence of misuse of the prescribed medications, the incidence of diversion of the prescribed medications, and the incidence of SUD in this population?
Key Question 2 | Among adults diagnosed with ADHD with a co-occurring SUD, what are the benefits and harms of non-stimulant ADHD pharmacological and/or nonpharmacological treatment of ADHD compared to ADHD psychostimulant medications?

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (CRD42024517093 (https://www.crd.york.ac.uk/prospero/display_record.php?RecordID=517093)).

## SEARCHING AND STUDY SELECTION

We conducted a preliminary search in Medline (via PubMed) that was focused on medical subject headings (MeSH) and free text terms for ADHD, SUD, misuse, diversion, and psychostimulant medications. We adapted search strategies from several related systematic reviews^36,46,52–60^ and worked with subject matter experts and the topic nominator to identify terms related to psychostimulant medications for ADHD.

For our final searches, we searched Medline (via PubMed), Embase, and PsycINFO from inception to December 14, 2023, in the Cochrane library from inception to January 30, 2024, and ClinicalTrials.gov from inception to February 23, 2024 (see Appendix A for complete search strategies). Citations for relevant systematic reviews were identified from hand-searching reference lists. A draft version of this report was reviewed by external peer reviewers; their comments and author responses are located in Appendix K.

Citations were entered into EndNote, where duplicates were removed. We screened citation in Systematic Review Data Repository (SRDR+ (https://srdrplus.ahrq.gov/)) which has machine learning algorithms to prioritize relevant citations. Based on empirical evidence, we stopped screening when all remaining unscreened abstracts had a prediction value of <0.40 (on a 0–1 scale), and subsequently 400 abstracts in a row were rejected. To ensure common understanding of the eligibility criteria among the research team, we ran 5 pilot rounds of 100 citations, where all team members screened the title and abstract of the same citations, and conflicts were resolved as a group. After the pilot rounds, citations were screened in duplicate with conflicts resolved by group discussion or by the lead researcher. Accepted abstracts underwent full-text review using an evidence mapping process by 1 researcher with confirmation of excluded articles by a second researcher. When necessary, the reviewers consulted a third senior researcher. Appendix B lists studies excluded at the full-text review phase, along with the reason for their exclusion.

Study eligibility criteria are listed in Table 1. For both KQs, eligible studies were required to enroll people diagnosed with ADHD using Diagnostic and Statistical Manual of Mental Disorders (DSM)-IV through DSM 5-TR criteria or comparable criteria. Because of this, we excluded studies published before 1994 based on the publication date of the DSM-IV. To manage resources needed to address the topic, citations were excluded during abstract screening if the title or abstract did not state that the population included people with ADHD, did not explicitly mention the use of prescription stimulant medications, or did not include any explicit mention of substance use, medication misuse, or diversion. For both KQs, if the study sample included people with various psychological disorders, at least 80% of the baseline sample needed to be diagnosed with ADHD.

For KQ 1, our focus was on reporting incident SUD diagnosis, or misuse or diversion of prescribed psychostimulants in adulthood. To ensure studies reported incident SUD diagnoses, we excluded cross-sectional studies and studies where the sample had SUD at baseline. We also excluded studies that only evaluated self-reported substance use and not SUD diagnoses. For KQ 1, outcomes of interest needed to be assessed in adulthood (≥18 years of age). For studies with outcomes reported in both adolescents and adults, at least 80% of the outcomes needed to be reported in people ≥18 years of age. Studies that only reported mean age at baseline and total follow-up were excluded if the estimated mean age was <18 years. We included RCTs, nonrandomized comparative studies (NRCS), and single-group studies. To evaluate the overall incidence of SUD, we analyzed the stimulant arms from comparative studies and single-group studies. We used comparative studies to determine whether taking stimulant medication for ADHD increases the risk of SUD diagnosis in people without a SUD at baseline. Outcomes of misuse were operationalized as using medications not as directed (eg, dose, frequency, route of administration, or purpose, including poisoning or overdose) and diversion was operationalized as the sale, purchase, theft, or giving away of ADHD medication.

For KQ 2, eligible studies compared stimulant treatment alone to other ADHD treatments, placebo, or no treatment in people with both ADHD and SUD. All subjects had to be ≥18 years of age at baseline. We excluded studies that did not include people with both ADHD and SUD at baseline. For studies that included ADHD people with and without SUD at baseline, at least 80% of the baseline population had to have a diagnosis of SUD to be included. For KQ 2, we only included RCTs and NRCS.

Table 1 Eligibility Criteria

| Inclusion Criteria | Exclusion Criteria
Population | KQ 1: People diagnosed with ADHD using DSM-IV, IV-TR, 5, 5-TR or comparable criteria (eg, ICD codes, validated instruments) who have been prescribed psychostimulant medications for ADHD and are without a history or current diagnosis of ADHD medication misuse or diversion, or SUD; KQ 2: Adults ≥18 diagnosed with ADHD using DSM-IV, IV-TR, 5, 5-TR or comparable criteria (eg, ICD codes, validated instruments) with a history or current diagnosis of a SUD | KQs 1 & 2: Those without ADHD diagnosis (ie, just symptoms or self-diagnosed); KQ 1: History or current diagnosis of ADHD medication misuse or diversion, or SUD at the time of ADHD prescription; KQ 2:; - Adolescent/children/pediatric populations; - People without SUD; - People that only have SUDs relating to tobacco/nicotine or caffeine.
Exposure | KQ 1: Prescribed psychostimulant medications; KQ2 2: Prescribed psychostimulant medications for ADHD alone, including short- and long-acting types
Comparator | KQ 1: None/any; KQ 2:; - Non-psychostimulant pharmacological ADHD medication.; - Psychotherapeutic interventions intended to improve ADHD management skills and/or symptoms (eg, behavior management interventions like cognitive behavioral therapy); - Treatment as usual (including those that compare an experimental to standard dose of stimulants) or no treatment | KQ 2:; - Studies where the comparator includes the use of alternative medicine interventions (eg, yoga); - Nonpharmacologic interventions which do not focus on ADHD skills; - Nonpharmacologic interventions which are not conducted by trained clinicians; - Studies that only compare different stimulant types
Outcomes | KQ 1:; - ADHD medication misuse or diversion in adulthood (including poisoning/overdose); - Incident SUD/dependence/substance-related psychosis/abuse diagnosis in adulthood; KQ 2:; - Change in ADHD symptoms/severity; - Change in functional ability or impairment; - SUD relapse/misuse/ diversion; - Treatment adherence (SUD and ADHD); - Side effects; - Mortality; - Quality of life and satisfaction; - Other mental health diagnoses, including change in severity or symptoms | KQs 1& 2:; - Only report tobacco/nicotine or caffeine outcomes; - Outcomes not reported in adulthood
Timing | KQs 1 & 2: Studies conducted in/after 1994
Setting | KQ 1: Community setting; KQ 2: Outpatient, residential, or community settings | KQ 1 & 2: Incarcerated populations; KQ 2: Inpatient populations
Study Design | KQs 1 & 2:; - RCT; - NRCS; KQ 1: Single-group studies | KQs 1 & 2:; - Studies with fewer than 11 people meeting our inclusion criteria; - Cross-sectional studies; - Case report/case series, protocols, studies that do not report patient-level data; KQ 1: Studies with less than 3 months of follow-up; KQ 2: Non-comparative studies

Abbreviations. ADHD=attention-deficit/hyperactivity disorder; DSM=Diagnostic and Statistical Manual of Mental Disorders; ICD=International Classification of Diseases; KQ=key question; NRCS=non-randomized comparative study; SUD=substance use disorder; TR=text revision.

## DATA ABSTRACTION AND RISK OF BIAS ASSESSMENT

We created a data extraction form in SRDR+. For all KQs, we extracted the following data from eligible studies: study design, setting, sample size, population characteristics, methods for diagnosing ADHD, treatment details (eg, total stimulant dose), duration of follow-up, and outcomes of interest. All data extraction was first completed by 1 reviewer and then confirmed by a second reviewer, with consultation from other team members as needed.

Risk of bias was independently assessed by 1 reviewer using questions derived from the Cochrane Risk of Bias tool for RCTs and ROBINS-I (Risk of Bias In Non-randomized Studies – of Intervention tool for other study design) tools (Appendix C) and confirmed by a second. For NRCS, we evaluated what strategies were used to deal with potential confounders (low risk of bias if they used propensity scores, moderate risk of bias if they used multivariable regression, and high risk of bias if there were concerns about the adjusted analysis). We also evaluated whether the article was free of discrepancies and adequately defined patient eligibility criteria, interventions, and outcomes assessed. Studies were rated as low overall risk of bias if they were determined to be low risk of bias in all domains or unclear risk of bias for 1 domain. Studies were rated as moderate overall risk of bias if there was unclear risk of bias for ≥2 domains, or either high risk of bias for 1 domain but low risk of bias for all others, or high risk of bias for 1 domain and unclear risk of bias for ≥2 domains. Studies were rated as high overall risk of bias if they were rated as high risk of bias in ≥2 domains.

## SYNTHESIS AND STRENGTH OF EVIDENCE

For KQ 1, we examined the incidence of SUD among people diagnosed with ADHD who were prescribed stimulant medications. Additionally, we compared the incidence of SUD between those who were and were not prescribed stimulant medications. In this report, we categorize substance use disorder outcomes into 3 groups. Outcomes not focused on a specific substance (eg, cocaine) were classified as SUD. Outcomes specific to alcohol use were categorized as alcohol use disorder (AUD). Outcomes focused on specific drug use disorders or those examining drugs separately from alcohol were categorized as non-alcohol substance use or stimulant use disorders. The categorization of substance use outcomes in each study is described in Appendix G.

For KQ 2, we extracted outcomes from studies in people with co-occurring ADHD and SUD who were taking prescription stimulant medications versus a comparison group. We compared results in study groups using odds ratios (OR) and hazard ratios (HR) for dichotomous outcomes. When a study had 0 events in one group, we added 0.5 to all cells before calculating an OR. We compared continuous data using mean differences (MD) between interventions. When necessary, we estimated MDs and their standard deviations from reported data, including from reported medians and ranges. Adjusted analyses were preferentially extracted over unadjusted (crude) comparisons. Where there were at least 3 studies reporting results from sufficiently similar analyses (based on population, interventions, comparators, and outcomes), we conducted random-effects meta-analyses using the meta package for R version 4.3.0 (R Foundation for Statistical Computing, Vienna, Austria).^61^ Statistical heterogeneity is reported with the I^2^ statistic, which estimates the proportion of all variation in effects that is due to true differences in effects between studies.

We assessed certainty of evidence using the GRADE (Grading of Recommendations Assessment, Development and Evaluation) methodology.^62^ We compiled key study findings in evidence profiles, which provide the basis for determination of certainty of evidence and summarize conclusions for outcomes. Within each outcome, we considered the study design, the number of studies and participants, methodological limitations, directness of the evidence, precision of the findings, consistency across studies, and other issues. We did not GRADE outcomes only informed from noncomparative studies. In addition, we did not GRADE studies reporting the incidence of outcomes among persons prescribed stimulants for ADHD. However, for these studies we assessed the various GRADE domains to communicate information about the characteristics of the studies, but we did not provide an overall rating for how the incidence estimates compare with a reference incidence (eg, the corresponding incidence in the general population). For KQ 2 (comparison of outcomes in persons prescribed stimulants versus not), we provide overall assessments for the strength of the evidence. Outcomes with inconclusive results were rated as insufficient evidence.