# BACKGROUND

Attention-deficit/hyperactivity disorder (ADHD) is a neurodevelopmental condition that has been recorded in the medical literature for the last 2 centuries under various names.^1,^ ^2^ While diagnostic criteria for ADHD have evolved over time, symptoms of ADHD generally include inattention, hyperactivity, and/or impulsivity.^3,^ ^4^ Typically, ADHD symptoms initially appear in childhood, and nearly 50% of diagnosed children will continue to experience some symptoms into adulthood.^5–7^ Most research on ADHD has focused on children, but over the past decade there has been an increase in the documented prevalence and incidence of ADHD among adults.^8–10^ Moreover, despite the United States military having enrollment restrictions for people with ADHD,^11^ the prevalence and incidence of diagnoses of ADHD among Veterans has also increased.^12–14^ One retrospective study conducted in the Department of Veterans Affairs (VA) found the annual prevalence of ADHD diagnoses among Veterans increased 258% (from 0.23% to 0.84%) and annual incidence increased 240% (from 0.14% to 0.48%) between 2009 and 2016.^12^

The mechanism of ADHD is likely multimodal.^15,^ ^16^ People with ADHD may have structural or functional differences of the brain. These include reduced volume in areas of the brain, including the prefrontal cortex and reductions in the basal ganglia, which can impact factors such as impulsivity and cognition.^17,^ ^18^ Pharmaceutical treatments for ADHD, including prescription psychostimulants, are thought to target regulation of these neurotransmitters.^19^

Adults with ADHD can experience negative occupational consequences,^20–22^ financial burden,^23^ social problems,^24^ increased risk for other mental health diagnoses and higher mortality.^25,^ ^26^ ADHD has also been associated with high health care use and costs.^2,^ ^27^ Potential consequences of untreated ADHD in adults include an increased risk of substance use, criminality, psychiatric disorders, suicide ideation or attempts, and fractures.^28–30^ However, treating ADHD in adults also presents challenges given the population may have, or be at risk for, comorbid psychological disorders. Longitudinal studies have found a higher incidence of mental health disorders, including mood, anxiety, and personality disorders among military service members treated for ADHD.^14,^ ^31^ ADHD and substance use disorder (SUD) are frequently co-occurring. Previous research has found that up to 40% of ADHD people in the general population may have co-occurring SUD,^31^ and that over 20% of people with SUD have co-occurring ADHD.^6^ Dysregulation of dopamine, which can impact impulse control and inattention, is thought to be involved in both ADHD and SUD.^32,^ ^33^ However, concerns remain over whether certain treatments for ADHD can impact brain development in ways that may increase SUD risk.^34^

Prescription psychostimulants, such as methylphenidate and amphetamine-based products (eg, lisdexamfetamine), are first-line pharmacologic treatments for ADHD in adults.^35^ This is also true in the military, where 1 study found that approximately 60% of service members with ADHD were prescribed ADHD medications, and more than 79% of these were prescribed psychostimulants.^14^ Misuse and diversion of psychostimulants have been reported in previous literature, and there is concern these medications may increase the risk of developing a SUD.^34,^ ^36^ However, these studies have often explored misuse in people who were not prescribed ADHD medications, or have included older medications with higher misuse potential (typically immediate-release formulations, in contrast to extended-release or prodrug formulations that are now commonly prescribed).^36^ In addition, the age of participants in previous studies (adolescents and young adults in college) places them in an environment where diversion is both easier and in higher demand and this may not be consistent with the “adult” experience of ADHD.^37^ Still, because of the potential for misuse, caution has been urged when considering the use of stimulant medications for ADHD in people with SUD.^38,^ ^39^ Non-pharmacologic treatments may be alternatives to psychostimulants,^40^ but there is uncertainty in their effectiveness, especially in populations with co-occurring SUD.^41^ This is of particular concern within the VA, where, in 2021, nearly 16% of the population had an SUD in the previous year.^42^

Despite the growing number of adults with an ADHD diagnosis, and several guidelines outside of the US,^43,^ ^44^ to date there has never been a consensus clinical practice guideline for the treatment of adults with ADHD. Though existing systematic reviews have examined the use of stimulant medications in ADHD, or have examined the relationship between ADHD and SUD, none have focused on stimulant use and SUD in adults in non-inpatient populations.^45–51^ To inform guidance on the management of ADHD in Veterans, the Veterans Health Administration (VHA) Office of Mental Health (OMH) requested the following systematic review on the incidence of SUD in adults with ADHD who are prescribed psychostimulant medications as well as the benefits and harms of psychostimulant treatment of ADHD in adults with comorbid SUD.