# APPENDIX K PEER REVIEW COMMENTS AND RESPONSES

Comment Number | Reviewer Number | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | Thank you.
2 | 2 | No - The way the to KQ’s are written in the intro to the executive summary does not match how they are described in the key finding, which makes the key finding and the executive summary VERY hard to read.; Clarify definitions Substance use disorder categories used in the Executive Summary and Key findings sections: “general SUD”, “alcohol use disorder”, “other drug dependencies”, “other drug use disorder” the terms are confusing and make the bulleted findings in the Key findings section very hard to understand. | We edited the Executive Summary and key findings for consistency and clarity. We appreciate the thoughtful comments provided on the PDF version of the report.; At times, the literature used confusing language to describe substance use. The methods section (Executive Summary and Main Report) now describes how we operationalized the different descriptions of substance use in the literature. In addition, the revised report includes Appendix G, which describes how substance use is defined in the studies.
3 | 3 | Yes | Thank you.
4 | 4 | Yes | Thank you.
5 | 5 | Yes | Thank you.
6 | 6 | Yes | Thank you.
7 | 7 | Yes | Thank you.
8 | 11 | No - See comments below. | Thank you. We provide responses to the individual comments below.
Is there any indication of bias in our synthesis of the evidence?
9 | 1 | No | Thank you.
10 | 2 | No | Thank you.
11 | 3 | No | Thank you.
12 | 4 | No | Thank you.
13 | 5 | No | Thank you.
14 | 6 | No | Thank you.
15 | 7 | No | Thank you.
16 | 11 | No | Thank you.
Are you aware of any [underlined: published] or [underlined: unpublished] studies that we may have overlooked?
17 | 1 | No | Thank you.
18 | 2 | No | Thank you.
19 | 3 | No | Thank you.
20 | 4 | No | Thank you.
21 | 5 | No | Thank you.
22 | 6 | No | Thank you.
23 | 7 | No | Thank you.
24 | 11 | No | Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report.
25 | 1 | Page vii, line 30: Make “stimulants” singular. | We have fixed the typo.
26 | 1 | Page vii, line 44: OMHSP no long exists. It is now OMH | We have corrected this.
27 | 1 | Page viii, line 8: It should be DSM-5 (Arabic Numeral). | We have corrected this.
28 | 1 | Page viii, line 10: Remove comma. | We have fixed the typo.
29 | 1 | Page viii, line 41: Need to be specific about which medication dosing refers to, presumably methylphenidate. | Thank you. We revised the sentence for clarity. “(1 study reported a mean dose 41.7 mg of methylphenidate and another study a mean maximum dose of 58.7 mg).”
30 | 1 | Page viii, line 48: Change “report” to “reporting.” | We have fixed the typo.
31 | 1 | Page viii, line 55: It I unclear what the definition of “general SUD” is. | At times, the literature used confusing language to describe substance use. The methods section of the main report now describes how we operationalized the different descriptions of substance use in the literature. In addition, the revised report includes Appendix G, which describes how substance use is defined in the studies.; We have also provided the following text in the executive summary to help clarify:; Studies reported various substance use disorder outcomes for KQ1. Two studies reported SUD (ie, any substance), and 3 studies reported alcohol use disorder (AUD) diagnosis separately from SUDs. Finally, 2 studies reported non-alcohol substance use disorders or stimulant use disorders. When studies reported SUD, AUD or other non-alcohol substance use disorders it was not always clear whether these were mutually exclusive.
32 | 1 | Page x, line 28: Change “dually-diagnosed individuals” to “individuals with co-occurring SUD and ADHD.” | Thank you. We have revised the text accordingly.
33 | 1 | Page x, line 36: Change “opiate” to “opioid.” (“Opiate” refers to compounds occurring naturally in the poppy plant. “Opioid” includes the opiates and all other compounds that bind to opioid receptors.) | Thank you. We have revised the text accordingly.
34 | 1 | Page xi, line 30: Not clear why the terminology, “other drug dependencies” is introduced here or what it specifically means. Wouldn’t it be better to stick simply with “SUD?” | The methods section of the main report now describes how we operationalized the different descriptions of substance use in the literature. In addition, the revised report includes Appendix G, which describes how substance use is defined in the studies.; We have also provided the following text in the executive summary to help clarify:; Studies reported various substance use disorder outcomes for KQ1. Two studies reported SUD (ie, any substance), and 3 studies reported alcohol use disorder (AUD) diagnosis separately from SUDs. Finally, 2 studies reported non-alcohol substance use disorders or stimulant use disorders. When studies reported SUD, AUD or other non-alcohol substance use disorders it was not always clear whether these were mutually exclusive.
35 | 1 | Page 4, line 46: Change “SUD patients” to “patients with SUD” (less stigmatizing language). | We have corrected this.
36 | 1 | Page 4, line 57: Remove “for.” | We have fixed the typo.
37 | 1 | Page 6, line 8: It should be DSM-5 (Arabic Numeral). | We have corrected this.
38 | 1 | Table 1: It should be DSM-5 (Arabic Numeral). | We have corrected this.
39 | 1 | Table 1: Not clear why psychosis is included in outcomes. It is not mentioned in the text, and incidence of psychosis is a separate issue from incidence of SUD (though there could be overlap obviously). | Thank you for this comment. We have updated the table to clarify that this outcome is “substance-related psychosis.” Substance-related psychosis was identified by the technical expert panel as an important outcome to evaluate.
40 | 1 | Page 7, line 57: Remove “for.” | We have fixed the typo.
41 | 1 | Page 12, lines 15-17: Unless the medications are specified, dosage amounts are meaningless. Also, the dosages as reported don’t even make sense. How can the mean maintenance dose be higher than the mean maximum dose? | Thank you for this comment. We have revised the text for clarity.; Only 2 studies reported stimulant dosage (mean 41.7 mg methylphenidate;^70^ mean maximum dose of 58.7 mg methylphenidate^72^).
42 | 1 | Page 12, line 35: Please rewrite this confusing sentence. | This text has been removed due to other edits.
43 | 1 | Page 12, lines 45-53: Typically SUD would include alcohol use disorder. Throughout the manuscript confusion remains about overlap or non-overlap between what is being call SUD vs. AUD alone. It is unclear what “general SUD” means. It is not clear what “other drug disorders” is referring to. | Thank you for this comment. The methods section now describes how we addressed the different substance use measures described in the literature. We have also added Appendix G, which provides the study definition and our categorization of these outcomes.
44 | 1 | Page 17, lines 44-46: Please rewrite this sentence. | Thank you. This sentence now says: It was unclear whether the same participants were included in both outcomes.
45 | 1 | Page 18, line 16: Change “methadone-maintained patients” to “patients receiving methadone treatment for opioid use disorder.” | Thank you. We revised the text accordingly.
46 | 1 | Page 18, line 44: Change “were” to “was.” | We have fixed the typo.
47 | 1 | Page 21, lines 29-31: This sentence is hard to understand. | Thank you. This sentence now says: This RCT found no significant differences in people with >30% reduction in AARS (OR = 0.56, 95% CI [0.2, 1.51]) or those with a combined CGI < 3 and ≥30% reduction in AARS (OR = 0.58, 95% CI [0.13, 2.66]) between the methylphenidate with CBT and bupropion with CBT groups.
48 | 1 | Page 21, line 33: Change “RCTs” to “RCT.” | We have fixed the typo.
49 | 1 | Page 23, line 26: Change “opiate” to “opioid.” | Thank you. We have revised the text accordingly.
50 | 1 | Page 23, line 42: Change “methadone-maintained patients” to “patients receiving methadone treatment for opioid use disorder.” | Thank you. We have revised the text accordingly.
51 | 1 | Page 23, lines 43-46: It is confusing when higher levels of use are reported, but then odds ratios less than 1 are reported. | Thank you. We have revised the sentence for clarity.
52 | 1 | Page 23, lines 46-48: Not clear why, if the participants had amphetamine dependence, opiate outcomes would be reported. (In the past when urine drug testing was done, it detected only morphine and codeine, natural constituents of the opioid poppy; thus, “opiate” may be correct in this context.) | Thank you. This study included individuals with cocaine dependence and reported use of other substances and “opiates”. Based on an earlier comment, we revised the description of the trial: Another RCT (14 weeks) in people with comorbid ADHD and cocaine dependence reported no significant differences in illicit opioid use during the study between methylphenidate with CBT compared to placebo with CBT (OR = 1.00, 95% CI [0.06, 16.42]).
53 | 1 | Page 24, lines 24-28: What this sentence is trying to say is unclear. How can there be fewer days of alcohol use with no difference in mean days. Also not clear what the <60 gm vs. >60 gm is referring to unless it is heavy drinking days | Thank you; we revised the sentence for clarity:; One RCT of people with comorbid ADHD and amphetamine dependence reported significantly fewer days of alcohol use of <60g/day for those receiving methylphenidate with skills training compared to placebo with skills training at 13 weeks follow-up (MD = −11.0 days, 95% CI [−20.89, −1.11]). The same trial reported no significant difference in the mean number of days people used alcohol >60g/day between groups (MD = −3.80 days, 95% CI [−12.18, 4.58].
54 | 1 | Page 24, line 35: Change “methadone-maintained patients” to “patients receiving methadone treatment for opioid use disorder.” | We revised the text accordingly.
55 | 1 | Page 24, line 58: Change “methadone-maintained patients” to “patients receiving methadone treatment for opioid use disorder.” | We revised the text accordingly.
56 | 1 | Page 25, line 7: Change “methadone-maintained patients” to “patients receiving methadone treatment for opioid use disorder.” | We revised the text accordingly.
57 | 1 | Page 26, line 40: Add “a” before “large.” | We have fixed the typo.
58 | 1 | Page 26, line 44: Statistically is misspelled. | We have fixed the typo.
59 | 1 | Page 27, lines 6-7: Change “ADHD patients” to “patients with ADHD.” | We revised the text accordingly.
60 | 1 | Page 28, line 34: Change “verses” to “versus.” | We have fixed the typo.
61 | 1 | Page 28, line 54: Change “ADHD patients” to “patients with ADHD.” | We have corrected this.
62 | 1 | Page 29, line 27: Change “education” to “educating.” | We have fixed the typo.
63 | 1 | Page 30, line 42: Remove “a” before “standardized.” | We have fixed the typo.
64 | 1 | Page 30, line 50: Change “ADHD patients” to “patients with ADHD.” | We have corrected this.
65 | 1 | Page 31, lines 6-8: Change “dually-diagnosed individuals” to “individuals with co-occurring SUD and ADHD.” | We have corrected this.
66 | 1 | Page 31, line 34: Change “opiate” to “opioid.” | We have corrected this.
67 | 1 | Page 31, line 54: Again, not entirely clear what is intended by “other drug dependencies.” | The methods section now describes how we addressed the different substance use measures described in the literature. In addition, the revised report includes Appendix G, which describes how substance use is defined in the studies.
68 | 2 | 1. Key findings, “the effect of stimulants in people with co-occurring ADHD and SUD” section. The two bulleted statements of finding in this section are VERY difficult to understand and to differentiate. For this work to be impactful, these statements should be clarified. The difference appears to be the level of evidence (No Vs. Insufficient) and the outcomes evaluated. But as it is written this is VERY hard to untangle.; Statement 1: “There is no evidence of a difference in ADHD treatment adherence, substance use, SUD symptom change, or abstinence from substances in people with co-occurring ADHD and SUD who are vs are not prescribed stimulants (all with low confidence).”; My interpretation of this statement:; Among clinical trials enrolling People with co-occurring ADHD and SUD who are either prescribed Vs. NOT prescribed stimulants, there is no evidence of a difference in key health outcomes (ADHD Treatment Adherence, substance use, SUD symptom change, abstinence).; Statement 2: There is insufficient evidence for ADHD symptom change, SUD treatment adherence, misuse or diversion, and depression / anxiety outcomes in patients with co-occurring ADHD and SUD who are vs are not prescribed stimulants medications (all no conclusion).; My interpretation of this statement:; Among clinical trials enrolling People with co-occurring ADHD and SUD who are either prescribed Vs. NOT prescribed stimulants, There is insufficient evidence for ADHD symptom change, SUD treatment adherence, misuse or diversion, and depression / anxiety outcomes | Thank you. Your interpretation of these statements is correct, and we have edited the text for clarity.
69 | 2 | 2. One of our key clinical questions derived from provider in put is the risk of stimulant misuse and diversion among adults with ADHD who are prescribed stimulants. It appears there one study that evaluated these outcomes: “diversion (11%) or misuse (10% to 31% depending on definition of misuse)” but this study was not graded for evidence. Why? Given this clinical importance of this question to VA providers, why not highlight this in the key findings? Could highlight: (1) there was only one study, (2) this is why it was not graded, but (3) this is what the outcomes where. | The methods section (full report) describes our approach for grading studies. For outcomes only informed by single group studies we assessed the various GRADE domains to communicate information about the characteristics of the studies but did not provide an overall rating for outcomes.; We updated the key findings to highlight the findings from this study and we note the finding is from a small single group study.
70 | 2 | 3. Two sections of the results in the executive summary: these two section titles need to be written in a way the reader can clearly and easily differentiate them. In the first heading you have an outcome list (SUD, Misuse, Diversion) and in the second heading you have the group comparison but now outcomes. | Thank you for this helpful suggestion. We have revised the section headings accordingly.; The effect of stimulants on the incidence of substance use disorders (SUD), misuse and diversion in people with attention-deficit/hyperactivity disorder (ADHD) without SUD at baseline; And; The effect of stimulants on ADHD and SUD symptom and treatment outcomes in people with co-occurring ADHD and SUD.
71 | 2 | 4. First paragraph of the discussion is VERY confusing. I have made several comments directly on the PDF. | Thank you for your suggested comments on the PDF of the report. We edited the Discussion for clarity.
72 | 2 | 5. Implication for VA policies section: We tend not to develop “policies” on prescribing so as not to interfere with provider-patient decision making. We do develop “guidance” and “guidelines” and provide education on best practices. That is the point of this evidence synthesis. | Thank you for this important comment. We revised the Discussion (Executive Summary and Main Report) to indicate a need for “guidance and education” to clinicians treating ADHD, rather than a need for policy development.; “Given the increasing rates of ADHD diagnoses in the Veteran population, the VA needs to provide guidance and education is necessary for clinicians treating ADHD.”
73 | 3 | The review is very thorough and detailed and addresses areas of clinical practice that yearn for clarification.; The report indicates that varying definitions of ADHD and SUD were included, from various DSM versions, the ICD, and other diagnostic frameworks, noting that these criteria vary in the requirements needed for diagnosis. This variability can lead to differences in patient populations across studies, particularly concerning symptom presentation. The evolving nature of DSM criteria reflects the inherent complexities in diagnosis, where features are influenced by both genetic and environmental factors and often overlap with other disorders. This evolution is crucial because it directly impacts clinicians’ diagnostic confidence. Currently, the diagnostic nomenclature does not fully support confident decision-making, often leaving clinicians to navigate uncertainties in defining and differentiating conditions. As diagnostic criteria mature and become more reliable, achieving greater homogeneity, studies can more effectively address the questions central to this project. Improved diagnostic clarity will ultimately enhance clinical decision-making, fostering more confident and accurate prescribing practices.; Some considerations, most are merely grammatic | Thank you and we appreciate your concise summary of some of the limitations of this body of research.
74 | 3 | Page v111 line 46 47 - report should be reporting | We have fixed the typo.
75 | 3 | Page 4 line 57- Remove the word for | We have fixed the typo.
76 | 3 | Page 7 line 57 - remove the word for | We have fixed the typo.
77 | 3 | Page 8 line 17-20 - The writing was a bit unclear to me. Does this proposed change help and convey the intended message? “For Key Question 1, we examined the incidence of Substance Use Disorder (SUD) among individuals diagnosed with ADHD who were prescribed stimulant medications. Additionally, we compared the incidence of SUD between two groups: individuals with ADHD who were prescribed stimulant medications and those with ADHD who were not prescribed stimulant medications. | Thank you for this suggestion. We revised the text to clarify our meaning. “For KQ 1, we examined the incidence of SUD among people diagnosed with ADHD who were prescribed stimulant medications. Additionally, we compared the incidence of SUD between those who were and were not prescribed stimulant medications.”
78 | 3 | Page 28 line 27 - Different should be difference | We have fixed the typo.
79 | 3 | Page 28 line 35 the word versus and vs are both used in document | Thank you. We revised the text for consistency.
80 | 3 | Page 28 line 43 remove the word the | We have fixed the typo.
81 | 3 | Page 29 line - 27 education should be educating | We have fixed the typo.
82 | 3 | Page x line 27-29; “Fears that the use of stimulant medications in adults with ADHD can lead to a new SUD diagnosis or precipitate substance-related problems in dually-diagnosed individuals appear not to be broadly supported by the evidence”. This sentence suggests that some evidence offers some support - is that the intended message? It may not match a stated conclusion which reads, “There is no evidence that stimulant medication treatment for ADHD increases the risk of some SUD diagnoses. | Thank you. We revised the text for clarity. “Fears that the use of stimulant medications in adults with ADHD can lead to a new SUD diagnosis or precipitate substance-related problems in people with co-occurring SUD and ADHD appear not to be supported by the overall evidence.”; The conclusion has been updated to say, “However, the overall evidence does not indicate that stimulant medication treatment for ADHD increases the risk of SUD diagnoses.”
83 | 4 | I have had the pleasure to review this excellent manuscript by Rieke et al. The team from evidence synthesis program has done an comprehensive job of reviewing extant literature to answer key questions asked by the OMHSP. Authors have done well to categorize different levels of evidence available in the literature and have analyzed the results considering the strength and weakness of various studies looking at ADHD, SUD and medications. The manuscript is well organized into different sections, and it has excellent tables detailing and summarizing the information provided in the text.; Authors found that there was limited evidence in the current literature to answer key questions with a sufficient degree of confidence. This manuscript identified significant gaps in literature pertinent to veterans, ADHD treatment with medications in the context of misuse and substance use disorders and agree with heir call for future studies to address the gaps in knowledge for a key clinical area for Veterans and the VA.; While the manuscript is overall very impressive it does need to be revised as there are some points that need to be addressed.; Please see my itemized comments that need to be addressed by the authors: | Thank you.
84 | 4 | 1) Page v Line 1; -Working title of “ADHD among veterans” is misguiding as this review did not specifically address ADHD in veterans. Given the lack of studies looking at veterans with ADHD and SUD this title gives the false impression that the studies reviewed are from adult ADHD in veterans. I would recommend coming up with a more specific title based on the key questions asked answered. | Thank you. The revised title is now “ADHD and Substance Use Disorders in Adults”
85 | 4 | 2) Under Key Findings:; -Page viii Line 41 in the section; Effect of Stimulants on Incidence of SUD, Misuse and Diversion Authors state:; “2 studies reported information on dosing (mean maximum dose between 58.7mg and 60mg).”; - Its not clear which medication dose are the authors referring to. Please clarify which stimulant medication/drug is being referred to here. | Thank you. We revised the sentence for clarity. “(mean 41.7mg of methylphenidate in one study and a mean maximum dose between of 58.7mg).”
86 | 4 | 3) Pages ix-x; Under Discussion:; Authors state:; “Several previous studies on ADHD patients, including adolescents, have reported that exposure to ADHD medications, including stimulant medication, may reduce substance use issues later in life. Partially in support of these observations we found no evidence of a difference for alcohol use disorders or dependence between people with ADHD who were and were not prescribed stimulants.”; -These statements do not account for the study finding that there was no difference in SUD outcomes including use in those prescribed stimulant medications vs those not prescribed stimulants. Inference of partial support of observation in this instance gives the impression of selective use of evidence to support the claim. I would suggest revision of this statement based on the totality of the evidence gathered. | Thank you, this section has been edited due to other changes in the results. The text now states: “Given the available data, we concluded that among people prescribed stimulants for ADHD compared to people with ADHD who are not prescribed stimulants there is no evidence of a difference in the risk of developing an SUD, and evidence was insufficient to assess the effect of stimulant medications on AUD and other non-alcohol substance use disorders.”
87 | 4 | 4) Page x; Under the header Implications for VA Policy; Line 34-35 “ Absent more evidence of harm, prescribers should consider stimulant and non-stimulant medications for the treatment of adult ADHD.”; And Main report; Page 31; Line 7-9; “Absent more evidence of harm (ie, incident SUD diagnoses and/or increases in substance-related problems in dually-diagnosed individuals), prescribers should consider stimulant and non-stimulant medications for the treatment of adult ADHD.”; -While the review showed with a low level of evidence that there was no increased risk of harm, it equally showed (with a similar level of evidence) that there was no difference in response of stimulant medications over placebo over any of the ADHD and SUD outcome measures. Therefore authors’ inference and recommendations are based on some low level evidence of no harm and not on the entirety of the evidence gathered for this study and goes beyond the key questions and their findings specifically in the evidence synthesis and refers to literature not included/pertinent to this review to justify prescription of medications.; I strongly recommend changing the recommendations to something like “ Absent evidence of harm and benefits in the current synthesis, prescriber should consider stimulant and non-stimulant medications for the treatment of adult ADHD after a thorough risk benefit discussion with patients on a case by case basis.” I am merely providing an example of a more neutral statement. Authors could revise their statement such that it does not sound as an emphatic call to prescribe more stimulant or non stimulant medications without actually finding evidence for prescribing medications in their own synthesis. | Thank you and we agree. The revised text now states: “Therefore, prescribers should consider stimulant treatment or other treatments for ADHD after a thorough, individualized risk-benefit discussion with, as well as collaboration with members of the care team.”
88 | 4 | 5) Main report:; Under RESULTS:; Page 23 Line 41-49;; “One 12 week RCT, which included methadone-maintained patients with both adult ADHD and cocaine dependence/abuse, reported a higher proportion of weeks positive for opiates during the study for those in the methylphenidate group compared to placebo (OR = 0.74, 95% CI [0.55, 0.99]), but not compared to .56 bupropion (OR = 0.84, 95% CI[0.62, 1.13]) Another RCT (14 weeks) in patients with comorbid ADHD and amphetamine dependence reported no significant differences in illicit opiate use between 56 methylphenidate compared to placebo (OR = 1.00, 95% CI [0.06, 16.42]).”; -2 different studies here have the same reference # 56. Please check references closely. | Thank you. We have corrected the reference.
89 | 4 | 6) Under DISCUSSION; Page 29 Line 18-37; -A significant amount of this paragraph has been spent on information from the study related to education patients about harms. Education of patients is a very important aspect of harm reduction and should be emphasized. However, this could be done in a more succinct manner. I would recommend authors summarize the findings of the study more succinctly without reducing the point of emphasis while retaining the focus on key questions of the study. | We edited the paragraph with the aim of being concise. “Educating patients about the potential harms of medication misuse, including non-medical use, is important. Although many health providers agree that part of their responsibility is to educate patients about medications, a recent survey of family physicians and college health professionals found that less than 75% felt it was their responsibility to educate patients on the legal risks of misuse or on the effects of misuse on social lives or other relationships.”
90 | 4 | 7); Page 55 Line 23-26; Authors state:; “One RCT reported lower opiate use in patients taking methylphenidate compared to placebo, which may support the theory that individuals with ADHD may use substances to self-medicate or that the change in lifestyle when they are on stimulants may give them a reason to stop using opiates.”; -This inference by the authors appears to be selective use of evidence synthesized and appears to be conjectural. There were other studies in the evidence synthesis that showed no change in Opiate use among patients on stimulants vs placebo. It would be best if the authors revised this statement based on the entirety of evidence gathered. | Thank you. We have removed the text indicating that this may support the theory of self-medicating.
91 | 5 | [No comments] | Not applicable.
92 | 6 | There are 2 sections that discuss VA implications and “need for policy”. These aren’t referenced and I believe to be inappropriate for inclusion in this evidence summary. The authors of this evidence summary should do not have authority to suggest that VA develop policy on clinical issues and I am concerned that this report will be published in a public forum without proper review by VHA Executives who oversee policy development. The 2 sections I recommend removing or significantly editing include: line 25-26 on page x and also lines 57-13 on pages 30 and 31. | We revised the section on “Implications for VA Policy” (Executive Summary and Main Report) to note the need for VA to provide guidance and education to clinicians treating ADHD, rather than a need for policy development.
93 | 7 | First, thank you for this great review! | Thank you.
94 | 7 | x, line 25 or 26, I am not in favor a VA policy for this treatment as it might be too prescriptive, but I do think the VA needs to provide education and resources to clinicians treating ADHD and prescribing both stimulant and nonstimulant medications, and leadership needs to support clinicians who determine that stimulant prescribing is not indicated especially when a Veteran wants stimulants. | Thank you and we agree. We revised the section (Executive Summary and Main Report) to note the “Given the increasing rates of ADHD diagnoses in the Veteran population, the VA needs to provide guidance and education is necessary for clinicians treating ADHD.”
95 | 7 | 4, line 37 or 28, lisdex is an amphetamine (it just needs GI enzymes to cleave off lysine to make it active dextroamphetamine), so you might want to say “Prescription of psychostimulants, such as methylphenidate and amphetamine-based products, .. | Thank you. We revised the sentence accordingly: Prescription psychostimulants, such as methylphenidate and amphetamine-based products (eg, lisdexamfetamine),…”
96 | 7 | 4, line 46 nonpharmacologic treatments is often used synonymously with psychotherapeutic interventions, so consider deleting the parenthetical example | Thank you; we have removed the parenthetical example.
97 | 7 | 4, line 52, I might word that a little stronger: to date there has never been a consensus clinical practice guideline for the treatment of adults with ADHD. | Thank you. We have updated this sentence to include the suggested language.; “Despite the growing number of adults with an ADHD diagnosis, and several guidelines outside of the US, to date there has never been a consensus clinical practice guideline for the treatment of adults with ADHD.”
98 | 11 | General comments:; There are several different terminologies used re: substances (i.e., other drug dependencies, general SUD, other drug use disorders, substance use) and it makes for an unclear read to not know what these mean. For example, how does “general SUD” differ from “other drug use disorder?” | The methods section (Executive Summary and Main Report) now describes how we operationalized the different descriptions of substance use in the literature. In addition, the revised report includes Appendix G, which describes how substance use is defined in the studies.
99 | 11 | Vii:; Key findings don’t align well with the KQ and it makes for a confusing read. Bullet point #1: break this up into two. For the statistics provided, consider how to contextualize the finding – e.g., is there a comparator? | We have separated the first bullet and edited the text to clarify when data were obtained from single group or comparative studies. Note that the statistics provided in bullet point #1 are from single group studies.
100 | 11 | Bullet points #4 and $5 are difficult to understand the differences and I would suggest revising. | We revised bullet point #4 and #5 for clarity.
101 | 11 | Viii:; Method section: how are misuse and diversion being operationalized for this review? I would strongly consider spending time on the definitions in this section and then later on note how these definitions vary and how they were measured in these studies (e.g., self-report, prescriber determination, etc.). | Thank you. We revised the methods section (full report) to describe our operationalization of misuse and diversion. “Outcomes of misuse were operationalized as using medications not as directed (eg, dose, frequency, route of administration, or purpose, including poisoning or overdose) and diversion was operationalized as the sale, purchase, theft, or giving away of ADHD medication.”
102 | 11 | Line 43: provide M/SD for the 3-19 follow-up years. | Some of studies reported ranges for follow-up or we estimated follow-up duration based on information reported. Therefore, we chose to report the range rather than mean. We have added the following text based on your comment:; In 5 of these studies length of follow-up ranged from 3 to 19 years, with 4 of these having 10 or more years of follow-up. Two studies did not report length of follow-up.
103 | 11 | Line 59: The 10-31% range is large – I would consider breaking this out in more detail. How are these studies defining misuse and what does the % look like when using their definition? This detailed approach will help providers understand what the % means. I say this because providers are concerned about misuse and enhancing detail would be helpful. It may even be useful to consider including a summary table in the executive summary of this – by studying, including their definition of misuse, how it was measured, and %. | Thank you. Of note, only 1 single group study reported on diversion and misuse for KQ1. We have edited the text to provide additional details on how the study reported misuse and diversion.; “Only 1 small study reported on prescription stimulant diversion, with 11% of enrollees self-reporting diversion. The same study found that 22% of people took too much of their prescribed medication or misused it in some way, 10% got high on their medication, 16% skipped their medication to use alcohol or drugs, 31% used their medications with alcohol, and 5% experienced a reaction when using their ADHD medication and alcohol or drugs.”
104 | 11 | Ix:; Line 3: define “general SUD”; Line 7: define “other drug use disorders” | The methods section (Executive Summary and Main Report) now describes how we operationalized the different descriptions of substance use in the literature. In addition, the revised report includes Appendix G, which describes how substance use is defined in the studies.
105 | 11 | Lines 11-39: Consider splitting these results by RCT vs. NRCS and then providing an overall summary. | Thank you for this comment. To keep the Executive Summary succinct, we provide limited details on the study design. Interested readers can find detailed information on findings for specific studies (and their design) in the main report.
106 | 11 | Line 30: Is ADHD treatment adherence referring to medication? I ask since CBT/skills training was mentioned in 6 RCTs above. | We have specified “medication adherence” here.
107 | 11 | Line 31: how was SUD symptom change defined? Is this a clinically significant change or merely a change in their score/change score? | Thank you for your question. This was defined by a change in score in the Tiffancy craving scale and change in Clinical Global Improvement score for cocaine use. The Executive Summary provides a high-level summary of the findings. The Main Report and Appendix provides specific details on the names of the measures of SUD symptom change and how these changes were evaluated.
108 | 11 | Lines 31-34: Given SUD is broad, what do we know about specific substances (e.g., alcohol, opioids, cannabis)? | Thank you for your comment. While there were limited data on specific substance use disorders (e.g., opioids), the results section of the Main Report, and the accompanying appendix tables, provide details about the specific types of substance use disorders examined in the included studies.
109 | 11 | Lines 34-38: I would expand on this sentence for clarity. I would frame it in the same way as the prior sentence to show how many studies examined each of these aspects. | Thank you. We revised the statement accordingly.
110 | 11 | Line 48: “some substance use” – what does this mean? SUD or using substances? | Thank you. This sentence has been removed due to other edits.
111 | 11 | Line 55: “patient characteristics” – please provide some examples | We revised the text to provide examples of patient characteristics. “One study (NRCS) reported a higher incidence proportion of SUD in ADHD people treated with mixed medications (combination of stimulants and other medications).”
112 | 11 | Lines 57-58: I’m unsure we can make this claim, based on the evidence, re: “more severe forms of ADHD” unless the study reported that the additional medication was prescribed specifically the augment the stimulants effects. | Thank you. We have edited this sentence in the Executive Summary and Main Report to say:; “Therefore, it is possible people who received mixed medications may represent those with other comorbidities that may increase the risk of SUD.”
113 | 11 | X:; Lines 10-13: Doesn’t this just mean that findings were mixed? If you want to report how many were significantly different vs. not significantly different for specificity’s sake, you can do that in a parenthetical. How this is currently worded is somewhat confusing. | Thank you; we have updated this sentence to state “mixed findings.”
114 | 11 | Line 11: “prioritized outcomes” – define. | The “prioritized outcomes” were those identified by our operational partners during the development of the review protocol. We have updated this language to “outcomes of interest.”
115 | 11 | Lines 15-16: But are they using similar types of measures which can provide some insight – e.g., symptom severity measures? | You are correct that these provided insight into change; however, it was challenging to interpret findings across studies since different measures were used to assess symptom change. For instance, some studies used self-reported measures of symptom change, while some studies used observer reported measures. Further some measures were specific to symptom type and measures were further complicating the interpretation across studies.
116 | 11 | Line 19: “substance use” – define. | Thank you for this comment. Outcomes of substance use varied widely across studies. To keep the executive summary succinct, we have not provided details of these definitions here. Interested readers will be able to find the full details of the different substance use outcomes on pages 23-25 of the main report and Tables H9 and I5 of the appendix.
117 | 11 | Line 25: consider suggestion the development of guidelines for providers, not suggesting VA policy. I am unsure if I would advocate for VA-wide policy which would impact a provider’s practice in this way. | We agree and have revised the text accordingly. “Given the increasing rates of ADHD diagnoses in the Veteran population, the VA needs to provide guidance and education is necessary for clinicians treating ADHD.”
118 | 11 | Lines 26-30 (i.e., Fears that the use of stimulant medications in adults with ADHD can lead to a new SUD diagnosis or precipitate substance-related problems in dually-diagnosed individuals appear not to be broadly supported by the evidence. Although no study was explicitly conducted in Veterans or the VA, many of the findings and conclusions likely translate to the VA.”): consider putting this piece into your key findings. | Thank you for this comment. We have updated the Key findings to include a Clinical Implications section that more explicitly states this point.
119 | 11 | Lines 48-49: Given that the follow-ups range from 3-19 years, it actually seems like we’re missing the more proximal time period following the stimulant prescription - in the months and year after initiation. | Thank you for this comment. We revised the Discussion to comment on the timing of follow-up.; “Finally, studies generally conducted follow-up over a long period of time (in 4 of 5 studies follow-up was >10 years) and there were limited data on short term outcomes, such as those that may occur in the immediate months following stimulant initiation.”
120 | 11 | Lines 54-55: The primary findings surrounding a stimulant use disorder was not made clear earlier in the overview. | Thank you. We revised the text (executive summary, results and discussion) to note that studies addressing KQ 2 predominantly included people with ADHD and co-occurring stimulant use disorder.
121 | 11 | XI:; Lines 20-21: This seems to contradict the first sentence. | Thank you. This text has been changed due to other edits.
122 | 11 | Page 4, Line 53: Consider providing citations for the reviews. Can you also provide an overview of what they found specific to SUD, even if it was not the full focus of the review? | The text now references the systematic reviews we referred to the sentence.
123 | 11 | Page 5, Line 10: “alcohol misuse” was included – I thought this was only including SUD? | Thank you. This has been corrected to “abuse.”
124 | 11 | Page 9: Why was data excluded pre-1994? I would consider providing a rationale. | We have included the following text in the methods to address note our rationale for excluding studies pre-1994:; “Because of this, we excluded studies published before 1994 based on the publication date of the DSM-IV.”