# APPENDIX J ADVERSE EVENTS OUTCOMES

Author, Year, PMID | Outcome | Outcome Details | Population | Follow-Up | Group/Comparators | n/N (%) | Effect Size (95% CI), p-Value
Levin 2006 | Adverse Events | Fatigue | All | 12 w | Methylphenidate | 0/32 (0) | OR 0.13 (0.01, 2.70)^a^; p=0.190^a^
Levin 2006 | Adverse Events | Fatigue | All | 12 w | Placebo | 3^1^/33 (9) | OR 0.13 (0.01, 2.70)^a^; p=0.190^a^
| Adverse Events | Increased sweating | All | 12 w | Methylphenidate | 2^1^/32 (6) | OR 0.67 (0.10, 4.28)^a^; p=0.669^a^
| Adverse Events | Increased sweating | All | 12 w | Bupropion | 3^1^/33 (9) | OR 0.67 (0.10, 4.28)^a^; p=0.669^a^
| Adverse Events | Ended trial due to side effects | All | 12 w | Methylphenidate | 1/32 (3) | OR 0.50 (0.04, 5.80)^a^; p=0.579^a^
| Adverse Events | Ended trial due to side effects | All | 12 w | Placebo | 2/33 (6) | OR 0.50 (0.04, 5.80)^a^; p=0.579^a^
| Adverse Events | Had dosage lowered during study | All | 12 w | Methylphenidate | 3/32 (9) | OR 3.31 (0.33, 33.63)^a^; p=0.312^a^
| Adverse Events | Had dosage lowered during study | All | 12 w | Bupropion | 1/33 (3) | OR 3.31 (0.33, 33.63)^a^; p=0.312^a^
Levin 2015; 25887096 | Adverse Events | Tolerated the assigned dose | Completed induction | 14 w | Mixed amphetamine salts | 53/81 (65%) | OR 0.27 (0.09, 0.77)^a^; p=0.014^a^
Levin 2015; 25887096 | Adverse Events | Tolerated the assigned dose | Completed induction | 14 w | Placebo | 35/40 (88%) | OR 0.27 (0.09, 0.77)^a^; p=0.014^a^
| Adverse Events | Medication discontinuation due to intolerable adverse effects or to blood pressure or heart rate above strict study parameters | All | 14 w | Mixed amphetamine salts | 12/83 (14%) | OR 1.65 (0.50, 5.46)^a^; p=0.413^a^
| Adverse Events | Medication discontinuation due to intolerable adverse effects or to blood pressure or heart rate above strict study parameters | All | 14 w | Placebo | 4/43 (10%) | OR 1.65 (0.50, 5.46)^a^; p=0.413^a^
| Adverse Events | Anxiety | All | 14 w | Mixed amphetamine salts | 13/83 (16%) | OR 2.48 (0.67, 9.22)^a^; p=0.176^a^
| Adverse Events | Anxiety | All | 14 w | Placebo | 3/43 (7%) | OR 2.48 (0.67, 9.22)^a^; p=0.176^a^
| Adverse Events | Insomnia | All | 14 w | Mixed amphetamine salts | 12/83 (14%) | OR 7.1 (0.89, 56.56)^a^; p=0.064^a^
| Adverse Events | Insomnia | All | 14 w | Placebo | 1/43 (2.3%) | OR 7.1 (0.89, 56.56)^a^; p=0.064^a^
| Adverse Events | Dry Mouth | All | 14 w | Mixed amphetamine salts | 12/83 (14%) | OR 14.86 (0.86, 257.43)^a^; p=0.064^a^
| Adverse Events | Dry Mouth | All | 14 w | Placebo | 0/43 (0%) | OR 14.86 (0.86, 257.43)^a^; p=0.064^a^
| Adverse Events | Decreased appetite | All | 14 w | Mixed amphetamine salts | 9/83 (11%) | OR 5.11 (0.63, 41.73)^a^; p=0.128^a^
| Adverse Events | Decreased appetite | All | 14 w | Placebo | 1/43 (2.3%) | OR 5.11 (0.63, 41.73)^a^; p=0.128^a^
| Adverse Events | Fidgety / Jittery | All | 14 w | Mixed amphetamine salts | 5/83 (6%) | OR 2.69 (0.3, 23.81)^a^; p=0.373^a^
| Adverse Events | Fidgety / Jittery | All | 14 w | Placebo | 1/43 (2.3%) | OR 2.69 (0.3, 23.81)^a^; p=0.373^a^
| Adverse Events | Headache | All | 14 w | Mixed amphetamine salts | 2/83 (2%) | OR 0.33 (0.05, 2.05)^a^; p=0.234^a^
| Adverse Events | Headache | All | 14 w | Placebo | 3/43 (7.0%) | OR 0.33 (0.05, 2.05)^a^; p=0.234^a^
| Adverse Events | Racing Heart | All | 14 w | Mixed amphetamine salts | 4/83 (5%) | OR 2.13 (0.23, 19.64)^a^; p=0.506^a^
| Adverse Events | Racing Heart | All | 14 w | Placebo | 1/43 (2.3%) | OR 2.13 (0.23, 19.64)^a^; p=0.506^a^
| Adverse Events | Fatigue | All | 14 w | Mixed amphetamine salts | 4/83 (5%) | OR 4.81 (0.25, 91.5)^a^; p=0.296^a^
| Adverse Events | Fatigue | All | 14 w | Placebo | 0/43 (0%) | OR 4.81 (0.25, 91.5)^a^; p=0.296^a^
| Adverse Events | Nausea | All | 14 w | Mixed amphetamine salts | 1/83 (1%) | OR 0.51 (0.03, 8.39)^a^; p=0.639^a^
| Adverse Events | Nausea | All | 14 w | Placebo | 1/43 (2%) | OR 0.51 (0.03, 8.39)^a^; p=0.639^a^
| Adverse Events | Breathing Difficulty | All | 14 w | Mixed amphetamine salts | 2/83 (2%) | OR 2.61 (0.12, 55.55)^a^; p=0.539^a^
| Adverse Events | Breathing Difficulty | All | 14 w | Placebo | 0/43 (0%) | OR 2.61 (0.12, 55.55)^a^; p=0.539^a^
| Adverse Events | Chest Palpitations | All | 14 w | Mixed amphetamine salts | 1/83 (1%) | OR 0.51 (0.03, 8.39)^a^; p=0.639^a^
| Adverse Events | Chest Palpitations | All | 14 w | Placebo | 1/43 (2%) | OR 0.51 (0.03, 8.39)^a^; p=0.639^a^
| Adverse Events | Chest Pain | All | 14 w | Mixed amphetamine salts | 1/83 (1%) | OR 0.51 (0.03, 8.39)^a^; p=0.639^a^
| Adverse Events | Chest Pain | All | 14 w | Placebo | 1/43 (2%) | OR 0.51 (0.03, 8.39)^a^; p=0.639^a^
| Adverse Events | Rash | All | 14 w | Mixed amphetamine salts | 2/83 (2%) | OR 2.61 (0.12, 55.55)^a^; p=0.539^a^
| Adverse Events | Rash | All | 14 w | Placebo | 0/43 (0%) | OR 2.61 (0.12, 55.55)^a^; p=0.539^a^
| Adverse Events | Itchiness | All | 14 w | Mixed amphetamine salts | 1/83 (1%) | OR 0.51 (0.03, 8.39)^a^; p=0.639^a^
| Adverse Events | Itchiness | All | 14 w | Placebo | 1/43 (2%) | OR 0.51 (0.03, 8.39)^a^; p=0.639^a^
| Adverse Events | Vomiting | All | 14 w | Mixed amphetamine salts | 1/83 (1%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
| Adverse Events | Vomiting | All | 14 w | Placebo | 0/43 (0%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
| Adverse Events | Depression | All | 14 w | Mixed amphetamine salts | 0/83 (0%) | OR 0.25 (0.01, 7.74)^a^; p=0.432^a^
| Adverse Events | Depression | All | 14 w | Placebo | 1/43 (2%) | OR 0.25 (0.01, 7.74)^a^; p=0.432^a^
| Adverse Events | Dizziness | All | 14 w | Mixed amphetamine salts | 1/83 (1%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
| Adverse Events | Dizziness | All | 14 w | Placebo | 0/43 (0%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
| Adverse Events | Diarrhea | All | 14 w | Mixed amphetamine salts | 1/83 (1%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
| Adverse Events | Diarrhea | All | 14 w | Placebo | 0/43 (0%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
| Adverse Events | Agitation | All | 14 w | Mixed amphetamine salts | 1/83 (1%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
| Adverse Events | Agitation | All | 14 w | Placebo | 0/43 (0%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
| Adverse Events | Obsessive thoughts | All | 14 w | Mixed amphetamine salts | 1/83 (1%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
| Adverse Events | Obsessive thoughts | All | 14 w | Placebo | 0/43 (0%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
| Adverse Events | Increased libido | All | 14 w | Mixed amphetamine salts | 1/83 (1%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
| Adverse Events | Increased libido | All | 14 w | Placebo | 0/43 (0%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
| Adverse Events | Sinus infection | All | 14 w | Mixed amphetamine salts | 1/83 (1%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
| Adverse Events | Sinus infection | All | 14 w | Placebo | 0/43 (0%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
| Adverse Events | Staph infection | All | 14 w | Mixed amphetamine salts | 1/83 (1%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
| Adverse Events | Staph infection | All | 14 w | Placebo | 0/43 (0%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
| Adverse Events | Shoulder pain | All | 14 w | Mixed amphetamine salts | 1/83 (1%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
| Adverse Events | Shoulder pain | All | 14 w | Placebo | 0/43 (0%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
| Adverse Events | Prickly sensation | All | 14 w | Mixed amphetamine salts | 0/83 (0%) | OR 0.25 (0.01, 7.74)^a^; p=0.432^a^
| Adverse Events | Prickly sensation | All | 14 w | Placebo | 1/43 (2%) | OR 0.25 (0.01, 7.74)^a^; p=0.432^a^
| Adverse Events | Back pain | All | 14 w | Mixed amphetamine salts | 1/83 (1%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
| Adverse Events | Back pain | All | 14 w | Placebo | 0/43 (0%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
| Adverse Events | Stomach pain | All | 14 w | Mixed amphetamine salts | 1/83 (1%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
| Adverse Events | Stomach pain | All | 14 w | Placebo | 0/43 (0%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
| Adverse Events | Possible seizure | All | 14 w | Mixed amphetamine salts | 1/83 (1%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
| Adverse Events | Possible seizure | All | 14 w | Placebo | 0/43 (0%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
| Adverse Events | Abscess | All | 14 w | Mixed amphetamine salts | 1/83 (1%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
| Adverse Events | Abscess | All | 14 w | Placebo | 0/43 (0%) | OR 1.55 (0.06, 38.75)^a^; p=0.791^a^
Levin 2007; 16930863 | Adverse Events | Headache (moderate/severe) | All | 14 w | Methylphenidate | 4.24/53 (8%) | OR 4.26 (0.49, 37.09)^a^; p=0.189^a^
Levin 2007; 16930863 | Adverse Events | Headache (moderate/severe) | All | 14 w | Placebo | 1.06/53 (2%) | OR 4.26 (0.49, 37.09)^a^; p=0.189^a^
| Adverse Events | Gastrointestinal upset (moderate/severe) | All | 14 w | Methylphenidate | 4.24/53 (8%) | OR 2.09 (0.38, 11.36)^a^; p=0.395^a^
| Adverse Events | Gastrointestinal upset (moderate/severe) | All | 14 w | Placebo | 2.12/53 (4%) | OR 2.09 (0.38, 11.36)^a^; p=0.395^a^
| Adverse Events | Diarrhea (moderate/severe) | All | 14 w | Methylphenidate | 1.06/53 (2%) | OR 0.21 (0.02, 1.76)^a^; p=0.148^a^
| Adverse Events | Diarrhea (moderate/severe) | All | 14 w | Placebo | 4.77/53 (9%) | OR 0.21 (0.02, 1.76)^a^; p=0.148^a^
| Adverse Events | Insomnia (moderate/severe) | All | 14 w | Methylphenidate | 4.77/53 (9%) | OR 4.85 (0.57, 41.22)^a^; p=0.148^a^
| Adverse Events | Insomnia (moderate/severe) | All | 14 w | Placebo | 1.06/53 (2%) | OR 4.85 (0.57, 41.22)^a^; p=0.148^a^
| Adverse Events | Stopped medication due to adverse events | All | 14 w | Methylphenidate | 1/53 (2%) | OR 1 (0.06, 16.42)^a^; p=1^a^
| Adverse Events | Stopped medication due to adverse events | All | 14 w | Placebo | 1/53 (2%) | OR 1 (0.06, 16.42)^a^; p=1^a^
| Adverse Events | Medication dose lowered due to adverse events | All | 14 w | Methylphenidate | 4/53 (8%) | OR 4.24 (0.46, 39.31)^a^; p=0.203^a^
| Adverse Events | Medication dose lowered due to adverse events | All | 14 w | Placebo | 1/53 (2%) | OR 4.24 (0.46, 39.31)^a^; p=0.203^a^
Schubiner 2002; 12233989 | Adverse Events | Chest pain | All | 12 w | Methylphenidate | 0/24 (0%) | OR 0.24 (0.01, 5.8)^a^; p=0.383^a^
Schubiner 2002; 12233989 | Adverse Events | Chest pain | All | 12 w | Placebo | 1.92/24 (8%) | OR 0.24 (0.01, 5.8)^a^; p=0.383^a^
| Adverse Events | Palpitations | All | 12 w | Methylphenidate | 0/24 (0%) | OR 0.51 (0.02, 16.35)^a^; p=0.704^a^
| Adverse Events | Palpitations | All | 12 w | Placebo | 0.96/24 (4%) | OR 0.51 (0.02, 16.35)^a^; p=0.704^a^
| Adverse Events | Dizzy | All | 12 w | Methylphenidate | 1.92/24 (8%) | OR 2.09 (0.17, 25.9)^a^; p=0.567
| Adverse Events | Dizzy | All | 12 w | Placebo | 0.96/24 (4%) | OR 2.09 (0.17, 25.9)^a^; p=0.567
| Adverse Events | Stomachaches | All | 12 w | Methylphenidate | 3.12/24 (13%) | OR 1 (0.19, 5.38)^a^; p=1^a^
| Adverse Events | Stomachaches | All | 12 w | Placebo | 3.12/24 (13%) | OR 1 (0.19, 5.38)^a^; p=1^a^
| Adverse Events | Nightmares | All | 12 w | Methylphenidate | 5.04/24 (21%) | OR 1.78 (0.38, 8.32)^a^; p=0.464^a^
| Adverse Events | Nightmares | All | 12 w | Placebo | 3.12/24 (13%) | OR 1.78 (0.38, 8.32)^a^; p=0.464^a^
| Adverse Events | Headaches | All | 12 w | Methylphenidate | 6/24 (25%) | OR 1 (0.27, 3.69)^a^; p=1^a^
| Adverse Events | Headaches | All | 12 w | Placebo | 6/24 (25%) | OR 1 (0.27, 3.69)^a^; p=1^a^
| Adverse Events | Nausea or upset stomach | All | 12 w | Methylphenidate | 7.92/24 (33%) | OR 1.85 (0.51, 6.8)^a^; p=0.352^a^
| Adverse Events | Nausea or upset stomach | All | 12 w | Placebo | 5.04/24 (21%) | OR 1.85 (0.51, 6.8)^a^; p=0.352^a^
| Adverse Events | Euphoric, unusually happy | All | 12 w | Methylphenidate | 10.08/24 (42%) | OR 1.77 (0.54, 5.87)^a^; p=0.349^a^
| Adverse Events | Euphoric, unusually happy | All | 12 w | Placebo | 6.96/24 (29%) | OR 1.77 (0.54, 5.87)^a^; p=0.349^a^
| Adverse Events | Drowsiness | All | 12 w | Methylphenidate | 6/24 (25%) | OR 0.46 (0.13, 1.57)^a^; p=0.216^a^
| Adverse Events | Drowsiness | All | 12 w | Placebo | 10.08/24 (42%) | OR 0.46 (0.13, 1.57)^a^; p=0.216^a^
| Adverse Events | Tics or nervous movements | All | 12 w | Methylphenidate | 4.08/24 (17%) | OR 0.77 (0.18, 3.28)^a^; p=0.724^a^
| Adverse Events | Tics or nervous movements | All | 12 w | Placebo | 5.04/24 (21%) | OR 0.77 (0.18, 3.28)^a^; p=0.724^a^
| Adverse Events | Decreased appetite | All | 12 w | Methylphenidate | 12/24 (50%) | OR 3.00 (0.88, 10.18)^a^; p=0.078^a^
| Adverse Events | Decreased appetite | All | 12 w | Placebo | 6/24 (25%) | OR 3.00 (0.88, 10.18)^a^; p=0.078^a^
| Adverse Events | Insomnia or trouble sleeping | All | 12 w | Methylphenidate | 15.12/24 (63%) | OR 3.46 (1.05, 11.34)^a^; p=0.041^a^
| Adverse Events | Insomnia or trouble sleeping | All | 12 w | Placebo | 7.92/24 (33%) | OR 3.46 (1.05, 11.34)^a^; p=0.041^a^
| Adverse Events | Irritability | All | 12 w | Methylphenidate | 13.92/24 (58%) | OR 1.18 (0.38, 3.68)^a^; p=0.78^a^
| Adverse Events | Irritability | All | 12 w | Placebo | 12.96/24 (54%) | OR 1.18 (0.38, 3.68)^a^; p=0.78^a^
| Adverse Events | Sadness | All | 12 w | Methylphenidate | 15.12/24 (63%) | OR 2.78 (0.86, 8.94)^a^; p=0.087^a^
| Adverse Events | Sadness | All | 12 w | Placebo | 9.12/24 (38%) | OR 2.78 (0.86, 8.94)^a^; p=0.087^a^
| Adverse Events | Talk less with others | All | 12 w | Methylphenidate | 11.04/24 (46%) | OR 0.85 (0.27, 2.65)^a^; p=0.782
| Adverse Events | Talk less with others | All | 12 w | Placebo | 12/24 (50%) | OR 0.85 (0.27, 2.65)^a^; p=0.782
| Adverse Events | Stare a lot or daydreaming | All | 12 w | Methylphenidate | 12/24 (50%) | OR 0.41 (0.12, 1.34)^a^; p=0.14^a^
| Adverse Events | Stare a lot or daydreaming | All | 12 w | Placebo | 17.04/24 (71%) | OR 0.41 (0.12, 1.34)^a^; p=0.14^a^
| Adverse Events | Anxious | All | 12 w | Methylphenidate | 18.96/24 (79%) | OR 2.21 (0.61, 7.99)^a^; p=0.227^a^
| Adverse Events | Anxious | All | 12 w | Placebo | 15.12/24 (63%) | OR 2.21 (0.61, 7.99)^a^; p=0.227^a^
| Adverse Events | Medication dose lowered due to adverse events | All | 12 w | Methylphenidate | 6/24 (25%) | OR 3.83 (0.67, 21.84)^a^; p=0.13^a^
| Adverse Events | Medication dose lowered due to adverse events | All | 12 w | Placebo | 1.92/24 (8%) | OR 3.83 (0.67, 21.84)^a^; p=0.13^a^

Notes.

a Calculated by the research group, with 0.5 correction added to all cells when there were 0 events in 1 group.