# APPENDIX I CONTINUOUS OUTCOMES

Table I1 ADHD Treatment Adherence (KQ2, Continuous)

Author, Year, PMID | Outcome | Outcome Details | Population | Follow-Up | Group/Comparators | N | Mean (SD) or Median [25^th^, 75^th^ percentiles] | Effect Size (ES), p-Value
Levin 2007; 16930863 | ADHD Treatment Adherence | Proportion of samples with positive fluorescence | All | 14 w | Methylphenidate | 43 | 0.84 (0.16) | MD 0.02 (−0.05, 0.09)^a^; p=0.566^a^
Levin 2007; 16930863 | ADHD Treatment Adherence | Proportion of samples with positive fluorescence | All | 14 w | Placebo | 48 | 0.82 (0.17) | MD 0.02 (−0.05, 0.09)^a^; p=0.566^a^
Levin 2015; 25887096 | ADHD Treatment Adherence | Proportion of samples with positive fluorescence | All | 14 w | Mixed amphetamine salts (80mg) | 41 | 1 [0.897, 1] | ES: NR p=0.57
Levin 2015; 25887096 | ADHD Treatment Adherence | Proportion of samples with positive fluorescence | All | 14 w | Mixed amphetamine salts (60mg)_ | 38 | 1 [0.954, 1] | ES: NR p=0.57
Levin 2015; 25887096 | ADHD Treatment Adherence | Proportion of samples with positive fluorescence | All | 14 w | Placebo | 41 | 1 [0.929, 1] | ES: NR p=0.57

Notes.

a Calculated by the research group.

Abbreviations. ADHD=attention-deficit/hyperactivity disorder; ES=effect size; MD=mean difference; N=number; SD=standard deviation; w=weeks.

Table I2 SUD Treatment Adherence (KQ2, Continuous)

Author, Year, PMID | Outcome | Outcome Details | Population | Follow-Up | Group/Comparators | N | Mean (SD) or Median [25^th^, 75^th^ percentiles] | Effect Size (ES), p-Value
Levin 2015; 25887096 | SUD Treatment Adherence | Count of attended CBT sessions, out of 12 sessions | All | 14 w | Mixed amphetamine salts | 79 | 9.29 (3.88)^a^ | MD 1.19 (−0.36, 2.74)^a^; p=0.131^a^
Levin 2015; 25887096 | SUD Treatment Adherence | Count of attended CBT sessions, out of 12 sessions | All | 14 w | Placebo | 41 | 8.1 (4.4) | MD 1.19 (−0.36, 2.74)^a^; p=0.131^a^

Notes.

a Calculated by the research group.

Abbreviations. CBT=cognitive behavioral therapy; ES=effect size; MD=mean difference; N=number; SD=standard deviation; SUD=substance use disorder; w=weeks.

Table I3 SUD Symptom Change (KQ2, Continuous)

Author, Year, PMID | Outcome | Outcome Details | Population | Follow-Up | Group/Comparators | N | Mean (SD) or Median [25^th^, 75^th^ percentiles] | Effect Size (ES), p-Value
Konstenius 2010; 20015599 | Other Symptom Change | Change in craving [7-point visual analog craving scale adapted from the Tiffany craving scale] | All | 13 w | Methylphenidate | 12 | 2.3 (1.3) | MD −0.5 (−1.83, 0.83)^a^; p=0.670
Konstenius 2010; 20015599 | Other Symptom Change | Change in craving [7-point visual analog craving scale adapted from the Tiffany craving scale] | All | 13 w | Placebo | 12 | 2.8 (1.8) | MD −0.5 (−1.83, 0.83)^a^; p=0.670

Notes.

a Calculated by the research group.

Abbreviations. ES=effect size; MD=mean difference; N=number; SD=standard deviation; W=weeks.

Table I4 ADHD Symptom Change (KQ2, Continuous)

Author, Year, PMID | Outcome | Outcome Details | Population | Follow-Up | Group/Comparators | N | Mean (SD) or Median [25^th^, 75^th^ percentiles] | Effect Size (ES), p-Value
Konstenius 2010; 20015599 | ADHD Symptom Change | Change in CAARS (S) [Conners Adult ADHD Rating Scale; self-rated scale] | All | 13 w | Methylphenidate | 12 | 19.1^a^ (13.2) | MD 10.6 (−3.65, 24.85)^b^; p=0.137
Konstenius 2010; 20015599 | ADHD Symptom Change | Change in CAARS (S) [Conners Adult ADHD Rating Scale; self-rated scale] | All | 13 w | Placebo | 12 | 8.5^a^ (19.8) | MD 10.6 (−3.65, 24.85)^b^; p=0.137
Konstenius 2010; 20015599 | ADHD Symptom Change | Change in CAARS (O) [Conners Adult ADHD Rating Scale; observer-rated scale] | All | 13 w | Methylphenidate | 12 | 3.9^a^ (11.9) | MD −0.10 (−11.01, 10.81); p=0.686
Konstenius 2010; 20015599 | ADHD Symptom Change | Change in CAARS (O) [Conners Adult ADHD Rating Scale; observer-rated scale] | All | 13 w | Placebo | 12 | 4.0^a^ (13.8) | MD −0.10 (−11.01, 10.81); p=0.686
Levin 2015; 25887096 | ADHD Symptom Change | Change in the AISRS [Adult ADHD Investigator Symptom Rating Scale], Calculated as the value at week 0 minus the value at the last week | All | 14 w | Mixed amphetamine salts | 79 | 18.0 (12.2)^b^ | MD 9.41 (4.75, 14.07)^b^; p<0.001
Levin 2015; 25887096 | ADHD Symptom Change | Change in the AISRS [Adult ADHD Investigator Symptom Rating Scale], Calculated as the value at week 0 minus the value at the last week | All | 14 w | Placebo | 41 | 8.59 (12.24) | MD 9.41 (4.75, 14.07)^b^; p<0.001
Levin 2015; 25887096 | ADHD Symptom Change | Change in CGI psychopathology subscale for ADHD [Clinical Global Improvement], Calculated as the value at week 0 minus the value at the last week | All | 14 w | Mixed amphetamine salts | 79 | 1.44 (1.15)^b^ | MD 0.64 (0.19, 1.09)^b^; p=0.001
Levin 2015; 25887096 | ADHD Symptom Change | Change in CGI psychopathology subscale for ADHD [Clinical Global Improvement], Calculated as the value at week 0 minus the value at the last week | All | 14 w | Placebo | 41 | 0.80 (1.23) | MD 0.64 (0.19, 1.09)^b^; p=0.001
Levin 2015; 25887096 | ADHD Symptom Change | Change in CAARS (Total score) [Conners Adult ADHD Rating Scales], Calculated as the value at week 0 minus the value at the last week | All | 14 w | Mixed amphetamine salts | 76 | 16.1 (15.3)^b^ | MD 11.09 (5.48, 16.70)^b^; p<0.001
Levin 2015; 25887096 | ADHD Symptom Change | Change in CAARS (Total score) [Conners Adult ADHD Rating Scales], Calculated as the value at week 0 minus the value at the last week | All | 14 w | Placebo | 40 | 5.01 (12.84) | MD 11.09 (5.48, 16.70)^b^; p<0.001
Levin 2015; 25887096 | ADHD Symptom Change | Change in CAARS (Hyperactive) [Conners Adult ADHD Rating Scales], Calculated as the value at week 0 minus the value at the last week | All | 14 w | Mixed amphetamine salts | 77 | 14.30 (13.9)^b^ | MD 8.88 (3.33, 14.43)^b^; p=0.002
Levin 2015; 25887096 | ADHD Symptom Change | Change in CAARS (Hyperactive) [Conners Adult ADHD Rating Scales], Calculated as the value at week 0 minus the value at the last week | All | 14 w | Placebo | 39 | 5.42 (14.92) | MD 8.88 (3.33, 14.43)^b^; p=0.002
Levin 2015; 25887096 | ADHD Symptom Change | Change in CAARS (Inattentive) [Conners Adult ADHD Rating Scales], Calculated as the value at week 0 minus the value at the last week | All | 14 w | Mixed amphetamine salts | 77 | 14.9 (15.3)^b^ | MD 10.87 (5.34, 16.40)^b^; p<0.001
Levin 2015; 25887096 | ADHD Symptom Change | Change in CAARS (Inattentive) [Conners Adult ADHD Rating Scales], Calculated as the value at week 0 minus the value at the last week | All | 14 w | Placebo | 39 | 4.03 (11.66) | MD 10.87 (5.34, 16.40)^b^; p<0.001
Schubiner 2002; 12233989 | ADHD Symptom Change | No. inattentive symptoms | All | 12 w | Methylphenidate | 24 | 2.13 (2.85) | MD −0.70 (−2.39, 0.99)^b^; p=0.408^b^
Schubiner 2002; 12233989 | ADHD Symptom Change | No. inattentive symptoms | All | 12 w | Placebo | 24 | 2.83 (2.96) | MD −0.70 (−2.39, 0.99)^b^; p=0.408^b^
Schubiner 2002; 12233989 | ADHD Symptom Change | No. hyperactive symptoms | All | 12 w | Methylphenidate | 24 | 3.42 (2.67) | MD −1.36 (−3.07, 0.35)^b^; p=0.115^b^
Schubiner 2002; 12233989 | ADHD Symptom Change | No. hyperactive symptoms | All | 12 w | Placebo | 24 | 4.78 (3.18) | MD −1.36 (−3.07, 0.35)^b^; p=0.115^b^

Notes.

a The reported change score was a follow-up minus baseline score. To make it consistent with Levin’s 2015 study, we recalculated it as a baseline minus the follow-up score;

b Calculated by the research group.

Abbreviations. ADHD=attention-deficit/hyperactivity disorder; AISRS=Adult ADHD Investigator Symptom Rating Scale; CAARS(S)=Conners Adult ADHD Rating Scale; self-rated scale; CAARS(O)=Conners Adult ADHD Rating Scale- observer-rated scale; CGI=Clinical Global Improvement; ES=effect size; MD=mean difference; N=number; SD=standard deviation; w=weeks.

Table I5 Substance Use (KQ2, Continuous)

Author, Year, PMID | Outcome | Outcome Details | Population | Follow-Up | Group/Comparators | N | Mean (SD) or Median [25^th^, 75^th^ percentiles] | Effect Size (ES), p-Value
Konstenius 2010; 20015599 | Substance Use | Amphetamine use, days [positive urine toxicology] | All | 13 w | Methylphenidate | 12 | 10.6 (8.8) | MD 2.00 (−5.04, 9.04)^a^; p=0.472
Konstenius 2010; 20015599 | Substance Use | Amphetamine use, days [positive urine toxicology] | All | 13 w | Placebo | 12 | 8.6 (7.8) | MD 2.00 (−5.04, 9.04)^a^; p=0.472
Konstenius 2010; 20015599 | Substance Use | Other illicit drug use, days [positive urine toxicology] | All | 13 w | Methylphenidate | 12 | 4.1 (3.6) | MD 0.60 (−2.49, 3.69)^a^; p=0.501
Konstenius 2010; 20015599 | Substance Use | Other illicit drug use, days [positive urine toxicology] | All | 13 w | Placebo | 12 | 3.5 (3.7) | MD 0.60 (−2.49, 3.69)^a^; p=0.501
Konstenius 2010; 20015599 | Substance Use | Amphetamine use, days [self-reported] | All | 13 w | Methylphenidate | 12 | 4.6 (7.9) | MD 0.5 (−5.07, 6.07)^a^ p=0.698
Konstenius 2010; 20015599 | Substance Use | Amphetamine use, days [self-reported] | All | 13 w | Placebo | 12 | 4.1 (4.9) | MD 0.5 (−5.07, 6.07)^a^ p=0.698
Konstenius 2010; 20015599 | Substance Use | Other illicit drug use, days [self-reported] | All | 13 w | Methylphenidate | 12 | 0.5 (1.0) | MD −4.10 (−8.33, 0.13)^a^; p=0.160
Konstenius 2010; 20015599 | Substance Use | Other illicit drug use, days [self-reported] | All | 13 w | Placebo | 12 | 4.6 (7.0) | MD −4.10 (−8.33, 0.13)^a^; p=0.160
Konstenius 2010; 20015599 | Substance Use | Alcohol use <60 g/day, days | All | 13 w | Methylphenidate | 12 | 1.3 (2.0) | MD −11.00 (−20.89, −1.11)^a^; p=0.038
Konstenius 2010; 20015599 | Substance Use | Alcohol use <60 g/day, days | All | 13 w | Placebo | 12 | 12.3 (16.4) | MD −11.00 (−20.89, −1.11)^a^; p=0.038
Konstenius 2010; 20015599 | Substance Use | Alcohol use >60 g/day, days | All | 13 w | Methylphenidate | 12 | 4.2 (10.0) | MD −3.80 (−12.18, 4.58)^a^; p=0.184
Konstenius 2010; 20015599 | Substance Use | Alcohol use >60 g/day, days | All | 13 w | Placebo | 12 | 8.0 (9.8) | MD −3.80 (−12.18, 4.58)^a^; p=0.184
Konstenius 2010; 20015599 | Substance Use | Time to relapse, days (by urine sample) | All | 13 w | Methylphenidate | 12 | 3.33, CI= 2.2–5.4 | ES: NR p: NS
Konstenius 2010; 20015599 | Substance Use | Time to relapse, days (by urine sample) | All | 13 w | Placebo | 12 | 3.80, CI= 1.8–4.9 | ES: NR p: NS
Levin 2006; 16102908 | Substance Use | Proportion of positive weeks for any drug | All | 12 w | Methylphenidate | 32 | 0.94 (0.08) | MD 0.03 (−0.01, 0.07))^a^; p=0.161)^a^
Levin 2006; 16102908 | Substance Use | Proportion of positive weeks for any drug | All | 12 w | Placebo | 33 | 0.91 (0.09) | MD 0.03 (−0.01, 0.07))^a^; p=0.161)^a^
Levin 2006; 16102908 | Substance Use | Proportion of positive weeks for any drug | All | 12 w | Methylphenidate | 32 | 0.94 (0.08) | MD 0.01 (−0.03, 0.05)^a^; p=0.616^a^
Levin 2006; 16102908 | Substance Use | Proportion of positive weeks for any drug | All | 12 w | Bupropion | 33 | 0.93 (0.08) | MD 0.01 (−0.03, 0.05)^a^; p=0.616^a^
Levin 2006; 16102908 | Substance Use | Proportion of positive weeks for Cocaine | Current cocaine abusing/dependent individuals | 12 w | Methylphenidate | 13 | 0.86 (0.25) | MD 0.00 (−0.19, 0.19)^a^; p=1^a^
Levin 2006; 16102908 | Substance Use | Proportion of positive weeks for Cocaine | Current cocaine abusing/dependent individuals | 12 w | Placebo | 21 | 0.86 (0.28) | MD 0.00 (−0.19, 0.19)^a^; p=1^a^
Levin 2006; 16102908 | Substance Use | Proportion of positive weeks for Cocaine | Current cocaine Abusing/dependent individuals | 12 w | Methylphenidate | 13 | 0.86 (0.25) | MD −0.05 (−0.23, 0.13)^a^; p=0.569^a^
Levin 2006; 16102908 | Substance Use | Proportion of positive weeks for Cocaine | Current cocaine Abusing/dependent individuals | 12 w | Bupropion | 18 | 0.91 (0.23) | MD −0.05 (−0.23, 0.13)^a^; p=0.569^a^
Levin 2007; 16930863 | Substance Use | Proportion of weeks that were cocaine positive | All | 14 w | Methylphenidate | 43 | 0.73 (0.29) | MD 0.03 (−0.05, 0.15)^a^; p=0.623^a^
Levin 2007; 16930863 | Substance Use | Proportion of weeks that were cocaine positive | All | 14 w | Placebo | 48 | 0.70 (0.29) | MD 0.03 (−0.05, 0.15)^a^; p=0.623^a^
Levin 2007; 16930863 | Substance Use | Mean level of THC in urine samples, ng/ml | Patients x 14 weeks x 3 samples per week | 14 w | Methylphenidate | 1806^b^ | 413 (482) | MD 239.00 (216.54, 261.46)^a^; p<0.001^a^
Levin 2007; 16930863 | Substance Use | Mean level of THC in urine samples, ng/ml | Patients x 14 weeks x 3 samples per week | 14 w | Placebo | 2016^b^ | 174 (170) | MD 239.00 (216.54, 261.46)^a^; p<0.001^a^
Schubiner 2002; 12233989 | Substance Use | Proportion of urine samples tested negative for cocaine | All | 12 w | Methylphenidate | 24 | 0.50 (0.50) | MD 0.08 (−0.16, 0.32)^a^; p=0.512^a^
Schubiner 2002; 12233989 | Substance Use | Proportion of urine samples tested negative for cocaine | All | 12 w | Placebo | 24 | 0.42 (0.32) | MD 0.08 (−0.16, 0.32)^a^; p=0.512^a^

Notes.

a Calculated by the research team;

b Estimated as a product of arm sample size, total follow-up length in weeks, and a count of samples per week (N=3).

Abbreviations. ES=effect size; MD=mean difference; N=number; NS=not significant; SD=standard deviation; SUD=substance use disorder; THC=tetrahydrocannabinol; w=weeks.

Table I6 Abstinence (KQ2, Continuous)

Author, Year, PMID | Outcome | Outcome Details | Population | Follow-Up | Group/Comparators | N | Mean (SD) or Median [25^th^, 75^th^ percentiles] | Effect size (ES), p-Value
Konstenius 2010; 20015599 | Abstinence | Longest period of abstinence, days | All | 13 w | Methylphenidate | 12 | 4.6 (3.4) | MD 0.70 (−2.01, 3.41)^a^; p=0.614
Konstenius 2010; 20015599 | Abstinence | Longest period of abstinence, days | All | 13 w | Placebo | 12 | 3.9 (3.0) | MD 0.70 (−2.01, 3.41)^a^; p=0.614
Schubiner 2002; 12233989 | Abstinence | Longest continuous abstinence, days | All | 12 w | Methylphenidate | 24 | 5.17 (6.22) | MD 0.00 (−3.42, 3.42)^a^; p=1^a^
Schubiner 2002; 12233989 | Abstinence | Longest continuous abstinence, days | All | 12 w | Placebo | 24 | 5.17 (5.53) | MD 0.00 (−3.42, 3.42)^a^; p=1^a^

Notes.

a Calculated by the research team.

Abbreviations. ES=effect size; MD=mean difference; N=number; SD=standard deviation; w=weeks.

Table I7 Other Symptom Change (KQ2, Continuous)

Author, Year, PMID | Outcome | Outcome Details | Population | Follow-Up | Group/Comparators | N | Mean (SD) or Median [25^th^, 75^th^ percentiles] | Effect size (ES), p-Value
Konstenius 2010; 20015599 | Other Symptom Change | Change in Beck’s Depression Inventory | All | 13 w | Methylphenidate | 12 | −6.9 (9.8) | MD −7.30 (−14.18, −0.42)^a^; p=0.138
Konstenius 2010; 20015599 | Other Symptom Change | Change in Beck’s Depression Inventory | All | 13 w | Placebo | 12 | 0.4 (6.0) | MD −7.30 (−14.18, −0.42)^a^; p=0.138
Konstenius 2010; 20015599 | Other Symptom Change | Change in Beck’s Anxiety Inventory | All | 13 w | Methylphenidate | 12 | −0.5 (6.4) | MD −3.9 (−8.45, 0.65)^a^; p=0.098
Konstenius 2010; 20015599 | Other Symptom Change | Change in Beck’s Anxiety Inventory | All | 13 w | Placebo | 12 | 3.4 (4.1) | MD −3.9 (−8.45, 0.65)^a^; p=0.098
Konstenius 2010; 20015599 | Other Symptom Change | Change in Stroop-test [reaction time and directed attention] | All | 13 w | Methylphenidate | 12 | −2.6 (22.0) | MD 4.40 (−9.92, 18.72)^a^; p=0.193
Konstenius 2010; 20015599 | Other Symptom Change | Change in Stroop-test [reaction time and directed attention] | All | 13 w | Placebo | 12 | −7.0 (9.4) | MD 4.40 (−9.92, 18.72)^a^; p=0.193

Notes.

a Calculated by the research team.

Abbreviations. ES=effect size; MD=mean difference; N=number; SD=standard deviation; w=weeks.