# APPENDIX H CATEGORICAL OUTCOMES

Table H1 SUD Outcomes (KQ1) - Comparative

Author, Year, PMID | Outcome | Outcome Details | Population | Follow-up | Group/Comparators | n/N (%) | Effect Size (95% CI), p-Value
Biederman 2008; 18316421 | Substance Use Disorder | Alcohol Abuse Disorder [DSM-IV] | All | 10 y | Lifetime stimulant therapy | NR/92 (NR) | aHR 1.1 (0.6, 2.1); p = 0.66
Biederman 2008; 18316421 | Substance Use Disorder | Alcohol Abuse Disorder [DSM-IV] | All | 10 y | No stimulant therapy | NR/39 (NR) | aHR 1.1 (0.6, 2.1); p = 0.66
Biederman 2008; 18316421 | Substance Dependence | Alcohol Dependence Disorder [DSM-IV] | All | 10 y | Lifetime stimulant therapy | NR/92 (NR) | aHR 1.0 (0.5, 2.4); p = 0.93
Biederman 2008; 18316421 | Substance Dependence | Alcohol Dependence Disorder [DSM-IV] | All | 10 y | No stimulant therapy | NR/39 (NR) | aHR 1.0 (0.5, 2.4); p = 0.93
Biederman 2008; 18316421 | Substance Use Disorder | Drug Abuse Disorder [DSM-IV] | All | 10 y | Lifetime stimulant therapy | NR/92 (NR) | aHR 1.6 (0.8, 3.2); p = 0.23
Biederman 2008; 18316421 | Substance Use Disorder | Drug Abuse Disorder [DSM-IV] | All | 10 y | No stimulant therapy | NR/39 (NR) | aHR 1.6 (0.8, 3.2); p = 0.23
Biederman 2008; 18316421 | Substance Dependence | Drug Dependence Disorder [DSM-IV] | All | 10 y | Lifetime stimulant therapy | NR/92 (NR) | aHR 1.0 (0.4, 2.6); p = 0.96
Biederman 2008; 18316421 | Substance Dependence | Drug Dependence Disorder [DSM-IV] | All | 10 y | No stimulant therapy | NR/39 (NR) | aHR 1.0 (0.4, 2.6); p = 0.96
Chang 2014; 25158998 | Substance Use Disorder | Substance Abuse [Hospital visits or deaths with ICD-10 codes: F11–F16, F19; deaths, and convictions for a substance-related crime] | ≥20 y at baseline | 3 y | Stimulant therapy | NR/NR (NR) | aHR 0.97 (0.78, 1.20); p: NR
Chang 2014; 25158998 | Substance Use Disorder | Substance Abuse [Hospital visits or deaths with ICD-10 codes: F11–F16, F19; deaths, and convictions for a substance-related crime] | ≥20 y at baseline | 3 y | No stimulant therapy | NR/NR(NR) | aHR 0.97 (0.78, 1.20); p: NR
Steinhausen 2014; 24314850 | Substance Use Disorder | Substance Use Disorder [ICD-8: 303, 304; ICD-10: F1] | All | 15 y | Methylphenidate | 102/7314 (1.4%) | aHR 0.92 (0.74, 1.15); p: NR
Steinhausen 2014; 24314850 | Substance Use Disorder | Substance Use Disorder [ICD-8: 303, 304; ICD-10: F1] | All | 15 y | No medication | 72/6370 (1.1%) | aHR 0.92 (0.74, 1.15); p: NR
Steinhausen 2014; 24314850 | Substance Use Disorder | Substance Use Disorder [ICD-8: 303, 304; ICD-10: F1] | All | 15 y | Mixed medication | 627/5494 (11.4%) | aHR 1.48 (1.31, 1.69); p: NR
Steinhausen 2014; 24314850 | Substance Use Disorder | Substance Use Disorder [ICD-8: 303, 304; ICD-10: F1] | All | 15 y | No medication | 72/6370 (1.1%) | aHR 1.48 (1.31, 1.69); p: NR

Abbreviations. aHR=adjusted hazard ratio; DSM=Diagnostic and Statistical Manual of Mental Disorders; ICD=International Classification of Disease; n/N=number; NR=not reported; OR=odds ratio; y=year.

Table H2 SUD Outcomes (KQ1) - Single Group

Author, Year, PMID | Outcome | Outcome Details | Population | Follow-Up | Group/Comparators | n/N (%)
Dalsgaard 2014; 24090624 | Substance Use Disorder | Substance Use Disorder [Psychiatric admissions in adulthood due to substance use disorder (ICD-8 or ICD-10: 304 or F 11.x–19.x)] | All | At mean age of 31 (SD 6.6) | Methylphenidate or dexamphetamine in childhood | 11/208 (5.3%)
Dalsgaard 2014; 24090624 | Substance Use Disorder | Alcohol Abuse Disorder / Alcohol Dependence [Psychiatric admissions in adulthood due to alcohol use disorder or alcohol dependence (ICD-8 or ICD-10: 291, 303 or F 10.x)] | All | At mean age of 31 (SD 6.6) | Methylphenidate or dexamphetamine in childhood | 11/208 (5.3%)
Mannuzza 2008; 18381904 | Substance Use Disorder | Substance Use Disorder [DSM-III-R substance use disorder diagnosed in late adolescence or young adulthood] | ADHD group | At mean age of 25.3 (SD 1.3) | Methylphenidate | 80/176 (45.4%)
Mannuzza 2008; 18381904 | Substance Use Disorder | Alcohol Use Disorder [DSM-III-R] | ADHD group | At mean age of 25.3 (SD 1.3) | Methylphenidate | 49/176 (27.8%)
Mannuzza 2008; 18381904 | Substance Use Disorder | Non-Alcohol Substance Use Disorder [DSM-III-R] | ADHD group | At mean age of 25.3 (SD 1.3) | Methylphenidate | 65/176 (36.9%)
Mannuzza 2008; 18381904 | Substance Use Disorder | Stimulant Use Disorder [DSM-III-R] | ADHD group | At mean age of 25.3 (SD 1.3) | Methylphenidate | 43/176 (24.4%)
Torgersen 2013; 23104523 | Substance Use Disorder | Substance Use Disorder [DSM-IV; alcohol, amphetamines, cannabis and opiates] | ADHD with no comorbid SUD | 43 m | Methylphenidate | 0/52 (0%)
Wilens 2006; 16601645 | Substance Use Disorder | Substance Use Disorder [DSM-IV] | All | 10 y | Stimulants (96%) | 29/55 (53%)

Abbreviations. DSM=Diagnostic and Statistical Manual Of Mental Disorders; ICD=International Classification of Disease; m=months; n/N=number; SD=standard deviation; y=year

Table H3 Diversion or Misuse Outcomes (KQ1) - All Single Group

Author, Year, PMID | Outcome | Outcome Details | Population | Follow-Up | Group/Comparators | n/N (%)
Wilens 2006; 16601645 | ADHD Medication Diversion | Sold ADHD medication within the past 4 years | All | 10 y | Stimulants (96%) | 6/55 (11%)
Wilens 2006; 16601645 | ADHD Medication Misuse | Used too much of ADHD medication within the past 4 years | All | 10 y | Stimulants (96%) | 12/55 (22%)
Wilens 2006; 16601645 | ADHD Medication Misuse | Got high on ADHD medication within the past 4 years | All | 10 y | Stimulants (96%) | 5/55 (10%)
Wilens 2006; 16601645 | ADHD Medication Misuse | Misused ADHD medication within the past 4 years | All | 10 y | Stimulants (96%) | 12/55 (22%)
Wilens 2006; 16601645 | ADHD Medication Misuse | Skipped ADHD medication to use alcohol or drugs within the past 4 years | All | 10 y | Stimulants (96%) | 9/55 (16%)
Wilens 2006; 16601645 | ADHD Medication Misuse | Used ADHD medication with alcohol or drugs within the past 4 years | All | 10 y | Stimulants (96%) | 17/55 (31%)
Wilens 2006; 16601645 | ADHD Medication Misuse | Experienced a reaction with ADHD medication and alcohol or drugs within the past 4 years | All | 10 y | Stimulants (96%) | 3/55 (5%)

Abbreviations. ADHD=attention-deficit/hyperactivity disorder; n/N=number; y=year.

Table H4 ADHD Treatment Adherence (KQ2)

Author, Year, PMID | Outcome | Outcome Details | Population | Follow-Up | Group/Comparators | n/N (%) | Effect Size (95% CI), p-Value
Konstenius 2010; 20015599 | ADHD Treatment Adherence | Treatment retention | Treatment Completers | 13 w | Methylphenidate | 5^a^/12 (41%) | OR 3.65 (0.53, 25.01)^a^; p = 0.188^a^
Konstenius 2010; 20015599 | ADHD Treatment Adherence | Treatment retention | Treatment Completers | 13 w | Placebo | 2^a^/12 (16%) | OR 3.65 (0.53, 25.01)^a^; p = 0.188^a^
Levin 2006; 16102908 | ADHD Treatment Adherence | Treatment compliance by Riboflavin fluorescence testing | All | 12 w | Methylphenidate | NR/NR (77%) | ES: NR p: NR
Levin 2006; 16102908 | ADHD Treatment Adherence | Treatment compliance by Riboflavin fluorescence testing | All | 12 w | Placebo | NRNR (83%) | ES: NR p: NR
Levin 2006; 16102908 | ADHD Treatment Adherence | Treatment compliance by Riboflavin fluorescence testing | All | 12 w | Methylphenidate | NR/NR (77%) | ES: NR p: NR
Levin 2006; 16102908 | ADHD Treatment Adherence | Treatment compliance by Riboflavin fluorescence testing | All | 12 w | Bupropion | NR/NR (91%) | ES: NR p: NR

Notes.

a Calculated by the research group.

Abbreviations. ADHD=attention-deficit/hyperactivity disorder; ES=effect size; n/N=number; NR=not reported; OR=odds ratio; w=weeks.

Table H5 SUD Treatment Adherence (KQ2)

Author, Year, PMID | Outcome | Outcome Details | Population | Follow-Up | Group/Comparators | n/N (%) | Effect Size (95% CI), p-Value
Kast 2021; 33988929 | SUD Treatment Adherence | Treatment attrition | All | 90 days | Stimulants within 90 days of admission | 8^a^/171 (5%) | aHR: 0.59 (0.40, 0.87); p = 0.008
Kast 2021; 33988929 | SUD Treatment Adherence | Treatment attrition | All | 90 days | No stimulants within 90 days of admission | 11^a^/32 (35%) | aHR: 0.59 (0.40, 0.87); p = 0.008

Note.

a Calculated by the research group.

Abbreviations. aHR=adjusted hazard ratio; SUD=substance use disorder.

Table H6 SUD Symptom Change (KQ2)

Author, Year, PMID | Outcome | Outcome Details | Population | Follow-Up | Group/Comparators | n/N (%) | Effect Size (95% CI), p-Value
Levin 2007; 16930863 | SUD Symptom Change | Improved on the CGI [Clinical Global Improvement, score of <3 for cocaine use] | All | 14 w | Methylphenidate | 32/53 (60%) | OR 1.58 (0.73, 3.42)^a^; p = 0.24
Levin 2007; 16930863 | SUD Symptom Change | Improved on the CGI [Clinical Global Improvement, score of <3 for cocaine use] | All | 14 w | Placebo | 26/53 (49%) | OR 1.58 (0.73, 3.42)^a^; p = 0.24

Notes.

a Calculated by the research group.

Abbreviations. CGI=clinical global improvement scale; n/N=number; OR=odds ratio; SUD=substance use disorder; w=weeks.

Table H7 ADHD Symptom Change (KQ2)

Author, Year, PMID | Outcome | Outcome Details | Population | Follow-Up | Group/Comparators | n/N (%) | Effect Size (95% CI), p-Value
Levin 2006; 16102908 | ADHD Symptom Change | CGI [Clinical Global Improvement] score of <3 at the end of the study | All | 12 w | Methylphenidate | 6/32 (19%) | OR 0.36 (0.11, 1.10)^a^; p=0.072^a^
Levin 2006; 16102908 | ADHD Symptom Change | CGI [Clinical Global Improvement] score of <3 at the end of the study | All | 12 w | Placebo | 13/33 (39%) | OR 0.36 (0.11, 1.10)^a^; p=0.072^a^
Levin 2006; 16102908 | ADHD Symptom Change | CGI [Clinical Global Improvement] score of <3 at the end of the study | All | 12 w | Methylphenidate | 6/32 (19%) | OR 0.53 (0.17, 1.69)^a^; p=0.283^a^
Levin 2006; 16102908 | ADHD Symptom Change | CGI [Clinical Global Improvement] score of <3 at the end of the study | All | 12 w | Bupropion | 10/33 (30%) | OR 0.53 (0.17, 1.69)^a^; p=0.283^a^
Levin 2006; 16102908 | ADHD Symptom Change | ≥30% reduction in AARS [Adult ADHD Rating Scale] | All | 12 w | Methylphenidate | 11/32 (34%) | OR 0.63 (0.23, 1.71)^a^; p=0.363^a^
Levin 2006; 16102908 | ADHD Symptom Change | ≥30% reduction in AARS [Adult ADHD Rating Scale] | All | 12 w | Placebo | 15/33 (46%) | OR 0.63 (0.23, 1.71)^a^; p=0.363^a^
Levin 2006; 16102908 | ADHD Symptom Change | ≥30% reduction in AARS [Adult ADHD Rating Scale] | All | 12 w | Methylphenidate | 11/32 (34%) | OR 0.56 (0.2, 1.51)^a^; p=0.25^a^
Levin 2006; 16102908 | ADHD Symptom Change | ≥30% reduction in AARS [Adult ADHD Rating Scale] | All | 12 w | Bupropion | 16/33 (49%) | OR 0.56 (0.2, 1.51)^a^; p=0.25^a^
Levin 2006; 16102908 | ADHD Symptom Change | ≥30% reduction in AARS & improved on CGI [Adult ADHD Rating Scale; Clinical Global Improvement scale; score of <3] | All | 12 w | Methylphenidate | 3/32 (9%) | OR 0.38 (0.09, 1.64); p=0.197
Levin 2006; 16102908 | ADHD Symptom Change | ≥30% reduction in AARS & improved on CGI [Adult ADHD Rating Scale; Clinical Global Improvement scale; score of <3] | All | 12 w | Placebo | 7/33 (21%) | OR 0.38 (0.09, 1.64); p=0.197
Levin 2006; 16102908 | ADHD Symptom Change | ≥30% reduction in AARS & improved on CGI [Adult ADHD Rating Scale; Clinical Global Improvement scale; score of <3] | All | 12 w | Methylphenidate | 3/32 (9%) | OR 0.58 (0.13, 2.66)^a^; p=0.482^a^
Levin 2006; 16102908 | ADHD Symptom Change | ≥30% reduction in AARS & improved on CGI [Adult ADHD Rating Scale; Clinical Global Improvement scale; score of <3] | All | 12 w | Bupropion | 5/33 (15%) | OR 0.58 (0.13, 2.66)^a^; p=0.482^a^
Levin 2007; 16930863 | ADHD Symptom Change | Much or very much improved on the GCI [Clinical Global Improvement scale for ADHD] | All | 14 w | Methylphenidate | 18/53 (34%) | OR 1.19 (0.53, 2.69)^a^; p=0.68
Levin 2007; 16930863 | ADHD Symptom Change | Much or very much improved on the GCI [Clinical Global Improvement scale for ADHD] | All | 14 w | Placebo | 16/53 (30%) | OR 1.19 (0.53, 2.69)^a^; p=0.68
Levin 2007; 16930863 | ADHD Symptom Change | ≥30% reduction in AARS [Adult ADHD Rating Scale] | All | 14 w | Methylphenidate | 25/53 (47%) | OR 0.74 (0.34, 1.59)^a^; p=0.44
Levin 2007; 16930863 | ADHD Symptom Change | ≥30% reduction in AARS [Adult ADHD Rating Scale] | All | 14 w | Placebo | 29/53 (55%) | OR 0.74 (0.34, 1.59)^a^; p=0.44
Levin 2007; 16930863 | ADHD Symptom Change | ≥30% reduction in AARS & improved on CGI [Adult ADHD Rating Scale; Clinical Global Improvement scale; score of <3] | All | 14 w | Methylphenidate | 16/53 (30%) | OR 1.10 (0.47, 2.53)^a^; p=0.83
Levin 2007; 16930863 | ADHD Symptom Change | ≥30% reduction in AARS & improved on CGI [Adult ADHD Rating Scale; Clinical Global Improvement scale; score of <3] | All | 14 w | Placebo | 15/53 (28%) | OR 1.10 (0.47, 2.53)^a^; p=0.83
Levin 2007; 16930863 | ADHD Symptom Change | ≥30% reduction on the TAADDS [Targeted Adult Attention Deficit Disorder Scale] | All | 14 w | Methylphenidate | 21/53 (40%) | OR 1.66 (0.74, 3.75)^a^; p=0.22
Levin 2007; 16930863 | ADHD Symptom Change | ≥30% reduction on the TAADDS [Targeted Adult Attention Deficit Disorder Scale] | All | 14 w | Placebo | 15/53 (28%) | OR 1.66 (0.74, 3.75)^a^; p=0.22
Levin 2015; 25887096 | ADHD Symptom Change | CGI [Clinical Global Impression score of <3 | All | 14 w | Mixed amphetamine salts | 31/83 (37%) | OR 4.53 (1.61, 12.73)^a^; p=0.004^a^
Levin 2015; 25887096 | ADHD Symptom Change | CGI [Clinical Global Impression score of <3 | All | 14 w | Placebo | 5/43 (12%) | OR 4.53 (1.61, 12.73)^a^; p=0.004^a^
Levin 2015; 25887096 | ADHD Symptom Change | ≥30% reduction in AISRS [Adult ADHD Investigator Symptom Rating Scale] | All | 14 w | Mixed amphetamine salts | 55/83 (66%) | OR 3.00 (1.40, 6.44)^a^; p=0.005^a^
Levin 2015; 25887096 | ADHD Symptom Change | ≥30% reduction in AISRS [Adult ADHD Investigator Symptom Rating Scale] | All | 14 w | Placebo | 17/43 (40%) | OR 3.00 (1.40, 6.44)^a^; p=0.005^a^
Schubiner 2002; 12233989 | ADHD Symptom Change | Moderate improvement by physician ratings (1 or 2 on 7-point scale | All | 12 w | Methylphenidate | 18.48/24 (77%) | OR 12.59 (3.21, 49.41)^a^; p<0.001^a^
Schubiner 2002; 12233989 | ADHD Symptom Change | Moderate improvement by physician ratings (1 or 2 on 7-point scale | All | 12 w | Placebo | 5.04/24 (21%) | OR 12.59 (3.21, 49.41)^a^; p<0.001^a^
Schubiner 2002; 12233989 | ADHD Symptom Change | Moderate improvement by patient ratings (1 or 2 on 7-point scale) | All | 12 w | Methylphenidate | 17.52/24 (73%) | OR 3.73 (1.11, 12.55)^a^; p=0.033^a^
Schubiner 2002; 12233989 | ADHD Symptom Change | Moderate improvement by patient ratings (1 or 2 on 7-point scale) | All | 12 w | Placebo | 10.08/24 (42%) | OR 3.73 (1.11, 12.55)^a^; p=0.033^a^

Notes.

a Calculated by the research group.

Abbreviations. AARS=Adult ADHD Rating Scale; ADHD=attention-deficit/hyperactivity disorder; AISRS=Adult ADHD Investigator Symptom Rating Scale; CGI=clinical global improvement; n/N=number; OR=odds ratio; TAADS=Targeted Adult Attention Deficit Disorder Scale; w=weeks.

Table H8 Abstinence (KQ2)

Author, Year, PMID | Outcome | Outcome Details | Population | Follow-Up | Group/Comparators | n/N (%) | Effect Size (95% CI), p-Value
Levin 2006; 16102908 | Abstinence | ≥2 consecutive weeks of abstinence | All | 12 w | Methylphenidate | 3/32 (9%) | OR 0.58 (0.13, 2.66)^a^; p=0.482^a^
Levin 2006; 16102908 | Abstinence | ≥2 consecutive weeks of abstinence | All | 12 w | Placebo | 5/33 (15%) | OR 0.58 (0.13, 2.66)^a^; p=0.482^a^
Levin 2006; 16102908 | Abstinence | ≥2 consecutive weeks of abstinence | All | 12 w | Methylphenidate | 3/32 (9%) | OR 1.60 (0.25, 10.29)^a^; p=0.619^a^
Levin 2006; 16102908 | Abstinence | ≥2 consecutive weeks of abstinence | All | 12 w | Bupropion | 2/33 (6%) | OR 1.60 (0.25, 10.29)^a^; p=0.619^a^
Levin 2006; 16102908 | Abstinence | ≥2 consecutive weeks of abstinence | Current cocaine abusing/dependent individuals | 12 w | Methylphenidate | 2/13 (15%) | OR 1.09 (0.16, 7.59)^a^; p = 0.95
Levin 2006; 16102908 | Abstinence | ≥2 consecutive weeks of abstinence | Current cocaine abusing/dependent individuals | 12 w | Placebo | 3/21 (14%) | OR 1.09 (0.16, 7.59)^a^; p = 0.95
Levin 2006; 16102908 | Abstinence | ≥2 consecutive weeks of abstinence | Current cocaine abusing/dependent individuals | 12 w | Methylphenidate | 2/13 (15%) | OR 1.45 (0.18, 11.94)^a^; p=0.727^a^
Levin 2006; 16102908 | Abstinence | ≥2 consecutive weeks of abstinence | Current cocaine abusing/dependent individuals | 12 w | Bupropion | 2/18 (11%) | OR 1.45 (0.18, 11.94)^a^; p=0.727^a^
Levin 2007; 16930863 | Abstinence | ≥2 consecutive weeks of abstinence | All | 14 w | Methylphenidate | 8/53 (15%) | OR 0.87 (0.31, 2.46)^a^; p=0.69
Levin 2007; 16930863 | Abstinence | ≥2 consecutive weeks of abstinence | All | 14 w | Placebo | 9/53 (17%) | OR 0.87 (0.31, 2.46)^a^; p=0.69
Levin 2015; 25887096 | Abstinence | ≥3 consecutive weeks of abstinence [by urine screens and self-report] | All | 14 w | Mixed amphetamine salts | 20/83 (24.1%) | aOR 8.74 (1.78, 42.97); p=0.008
Levin 2015; 25887096 | Abstinence | ≥3 consecutive weeks of abstinence [by urine screens and self-report] | All | 14 w | Placebo | 3/43 (7%) | aOR 8.74 (1.78, 42.97); p=0.008

Notes.

a Calculated by the research group.

Abbreviations. aOR=adjusted odds ratio; n/N=number; OR=odds ratio; w=weeks.

Table H9 Substance Use (KQ2)

Author, Year, PMID | Outcome | Outcome Details | Population | Follow-Up | Group/Comparators | n/N (%) | Effect Size (95% CI), p-Value
Levin 2006; 16102908 | Substance use | Proportion of weeks positive for opiates | Patients x 12 weeks | 12 w | Methylphenidate | 130/384 (34%) | OR 0.74 (0.55, 0.99)^a^; p=0.044^a^
Levin 2006; 16102908 | Substance use | Proportion of weeks positive for opiates | Patients x 12 weeks | 12 w | Placebo | 162/396 (41%) | OR 0.74 (0.55, 0.99)^a^; p=0.044^a^
Levin 2006; 16102908 | Substance use | Proportion of weeks positive for opiates | Patients x 12 weeks | 12 w | Methylphenidate | 130/384 (34%) | OR 0.84 (0.63, 1.13)^a^; p=0.245^a^
Levin 2006; 16102908 | Substance use | Proportion of weeks positive for opiates | Patients x 12 weeks | 12 w | Bupropion | 150/396 (38%) | OR 0.84 (0.63, 1.13)^a^; p=0.245^a^
Levin 2007; 16930863 | Substance Use | Probability of THC positive urine sample (>100 ng/ml) | All | 14 w | Methylphenidate | NR/53 (NR) | OR 2.56 (1.85, 3.57); p: NR^b^
Levin 2007; 16930863 | Substance Use | Probability of THC positive urine sample (>100 ng/ml) | All | 14 w | Placebo | NR/53 (NR) | OR 2.56 (1.85, 3.57); p: NR^b^
Levin 2007; 16930863 | Substance Use | Illicit amphetamine use | All | 14 w | Methylphenidate | 0/53 (0%) | OR 0.24 (0.01, 5.52)^a,c^; p=0.374^a^
Levin 2007; 16930863 | Substance Use | Illicit amphetamine use | All | 14 w | Placebo | 2/53 (4%) | OR 0.24 (0.01, 5.52)^a,c^; p=0.374^a^
Levin 2007; 16930863 | Substance Use | Illicit opiate use | All | 14 w | Methylphenidate | 1/53 (2%) | OR 1.00 (0.06, 16.42)^a^; p=1^a^
Levin 2007; 16930863 | Substance Use | Illicit opiate use | All | 14 w | Placebo | 1/53 (2%) | OR 1.00 (0.06, 16.42)^a^; p=1^a^
Notzon 2016; 28051838 | Substance Use | Cannabis smoking | All | 14 w | Mixed amphetamine salts | 18.13/37 (~49%)^d^ | OR 0.20 (0.05, 0.75)^a^; p=0.017^a^
Notzon 2016; 28051838 | Substance Use | Cannabis smoking | All | 14 w | Placebo | 16.60/20 (~83%)^d^ | OR 0.20 (0.05, 0.75)^a^; p=0.017^a^

Notes.

a Calculated by the research group;

b The study reported OR for Placebo vs Methylphenidate. The reported estimate was inverted to make the Placebo group a reference category;

c 0.5 correction for zero-cells;

d Percentages were extracted from the figure.

Abbreviations. NR=not reported; OR=odds ratio; THC=tetrahydrocannabinol; w=weeks.

Table H10 Medication Misuse or Diversion (KQ2)

Author, Year, PMID | Outcome | Outcome Details | Population | Follow-Up | Group/Comparators | n/N (%) | Effect Size (95% CI), p-Value
Levin 2006; 16102908 | ADHD Medication Diversion | ADHD Medication Diversion [any reports from counsellors, clinical staff or patients] | All | 12 w | Methylphenidate | 0/32 (0%) | Not applicable
Levin 2006; 16102908 | ADHD Medication Diversion | ADHD Medication Diversion [any reports from counsellors, clinical staff or patients] | All | 12 w | Placebo | 0/33 (0%) | Not applicable
Levin 2006; 16102908 | ADHD Medication Diversion | ADHD Medication Diversion [any reports from counsellors, clinical staff or patients] | All | 12 w | Methylphenidate | 0/32 (0%) | Not applicable
Levin 2006; 16102908 | ADHD Medication Diversion | ADHD Medication Diversion [any reports from counsellors, clinical staff or patients] | All | 12 w | Bupropion | 0/33 (0%) | Not applicable
Levin 2006; 16102908 | ADHD Medication Misuse | ADHD medication made them high or euphoric [any reports from counsellors, clinical staff or patients] | All | 12 w | Methylphenidate | 0/32 (0%) | Not applicable
Levin 2006; 16102908 | ADHD Medication Misuse | ADHD medication made them high or euphoric [any reports from counsellors, clinical staff or patients] | All | 12 w | Placebo | 0/33 (0%) | Not applicable
Levin 2006; 16102908 | ADHD Medication Misuse | ADHD medication made them high or euphoric [any reports from counsellors, clinical staff or patients] | All | 12 w | Methylphenidate | 0/32 (0%) | Not applicable
Levin 2006; 16102908 | ADHD Medication Misuse | ADHD medication made them high or euphoric [any reports from counsellors, clinical staff or patients] | All | 12 w | Bupropion | 0/33 (0%) | Not applicable

Abbreviations. ADHD=attention-deficit/hyperactivity disorder; n/N=number; w=weeks.